# APPENDIX B STUDY SELECTION

## Inclusion codes, code definitions, and criteria

1. Is the full text of the article in English?
  - Yes → Proceed to 2.
  - No → Code X1 (Non-English-language publication). STOP.
2. Does the population include Veterans with Gulf War Illness?
  Include: Veterans (either U.S. or international) deployed to the Persian Gulf region between Aug 2, 1990 - Nov 1991, defined by the authors as having Gulf War Illness according to a recognized case definition (CDC or Kansas), or defines cases using similar criteria to CDC/Kansas. Also include studies of civilian contractors present during the conflict, if available. Include studies where deployment status and/or time of deployment is unclear.
  Included illness definitions (past and present terms to identify Gulf War Illness): Chronic Multisymptom (or multisystem) Illness (CMI), Irritable Bowel Syndrome (IBS), Chronic Fatigue Syndrome (CFS)/Myalgic Encephalitis(ME), fibromyalgia (FM), Gulf War Syndrome.
  Exclude: children and birth outcomes of Gulf War Veterans.
  Comparator populations may include:
  - Veterans who were deployed elsewhere (other than Persian Gulf) during the Gulf War.
  - Gulf War-deployed Veterans
  - Non-deployed Gulf War era Veterans
  - Civilians with other health conditions/conditions with similar symptomology to GWI (eg, chronic fatigue syndrome, neurodegenerative disorders, musculoskeletal problems)
  - Healthy controls
  - Yes → Proceed to 3.
  - No → Code X2 (Excluded population). STOP.
3. Does the study examine measures of any of the following categories of biological functions/systems that are potential loci of dysfunction:
  ○ Genes (eg, paraoxonase levels, enzyme butyrylcholinesterase)
  ○ Immune activation/inflammation (eg, anti-squalene antibody, natural killer cell activity, humoral immune response, human leukocyte antigen, platelet function, plasma proteins, serum cytokines, peripheral blood lymphocyte factors)
  ○ Neurodegeneration (eg, acetylcholinesterase activity, N-acetylaspartate-to-creatine ratio)
  ○ Autonomic nervous system (eg, feedback regulation of the HPA axis)
  ○ Endocrine system (eg, neuroendocrine-immune signaling)
  ○ Energy metabolism (eg, mitochondrial dysfunction)
  ○ General brain activity (eg, synchronous neural interactions, findings from brain imaging (eg, fMRI, PET))
  ○ Other
  (Exclude: assessments that do not include biological measurements (eg, questionnaires, symptom inventories)
  - Yes → Proceed to 4.
  - No → Code X3 (Not relevant to GWI biological measures). STOP.
4. Is this study of diagnostic accuracy or a systematic review of such studies?
  - Yes →study of diagnostic accuracy. Code KQ1 diagnostic accuracy [specify test]. STOP.
  - Yes → Systematic review. Code KQ1-SR. STOP.
  - No → Proceed to 5.
5. Is the study a published measure of association between biological measures and GWI?
  - Yes → Code Bio-KQ2-[specify biological measure and biological measure category]. STOP.
  - No, it is an unpublished study that otherwise meets criteria → Code -KQ3 emerging research [specify biological measure and biological measure category]. STOP.
  - No, none of the above → Code X4. STOP.

[underlined: Key Questions:]

KQ1 Which diagnostic tests (or test combinations) are candidates for distinguishing individuals diagnosed with GWI from individuals without GWI?
KQ2 Which biological measures have been examined for their potential association with GWI, and which among them have been shown to be associated with GWI?
KQ3 Which ongoing or unpublished research studies examine diagnostic tests or biological measures for potential association with GWI?

[underlined: Exclusion Codes:]

- X1: Non-English-language publication
- X2: Excluded population
- X3: Not relevant to GWI biological measures/accuracy of tests
- X4: Excluded study design or publication type
- X9: Duplicate or preliminary publication of a more recent study
- X99: Study terminated