# APPENDIX A SEARCH STRATEGIES

## Ovid MEDLINE ALL 1946 to February 20, 2020

Date searched: February 21, 2020

1. Persian Gulf Syndrome/ or Gulf War/ (1100)
2. (“Desert Saber” or “Desert Sabre” or “Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Persian Gulf Syndrome” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab,kf. (2230)
3. (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab,kf. (222)
4. ((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) and (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or Veteran*)).ti,ab,kf. (2938)
5. or/1-4 (4955)
6. exp Biological measures/ (727323)
7. (antigen or antigens or autoantibod* or auto-antibod* or antibody or antibodies or bioassay* or bio-assay* or biological measure* or bio-marker* or biopsy or biopsies or blood or coexpress* or co-express* or conduction or “CT scan*” or cytokine or cytokines or diagnos* or dysfunction* or electromyograph* or endoscop* or fluid or fluids or fMRI or genet* or “gene expression” or imaging or inflammat* or marker or markers or MRI or “Magnetic resonance imaging” or mechanism* or neurodegenerat* or neuro-degenerat* or neuroendocrine or neuro-endocrine or neuroimag* or neuro-imag* or neuroinflammat* or neuro-inflammat* or protein or proteins or pulse or receptor or receptors or saliva or scan or scans or scanning or semen or serum or signal* or specimen* or temperature or test or tests or tissue* or tomograph* or ultrasound or urine or “vital signs” or x-ray*).ti,ab,kf. (14445351)
8. (bl or di or dg).fs. (4947785)
9. or/6-8 (16203250)
10. and/5,9 (2503)
11. 10 not ((exp animals/ not humans/) or (“animal model” or “animal models” or cat or cats or dog or dogs or marmoset* or mice or mouse or pig or pigs or rat or rats or rodent or sheep or species or swine or bTBI or mTBI or sTBI or PTSD or TBI or “post-traumatic stress” or “posttraumatic stress” or “traumatic brain injury” or “traumatic brain injuries”).ti.) (1773)
12. limit 11 to english language (1738)
13. limit 12 to yr="1990 -Current" (1736)

## PsycINFO 1806 to February Week 3 2020

Date searched: February 21, 2020

1. (“Desert Saber” or “Desert Sabre” or “Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Persian Gulf Syndrome” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab. (1135)
2. (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab. (64)
3. ((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) and (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or Veteran*)).ti,ab. (2431)
4. or/1-3 (3347)
5. Biological Markers/ (12461)
6. (antigen or antigens or autoantibod* or auto-antibod* or antibody or antibodies or bioassay* or bio-assay* or biological measure* or bio-marker* or biopsy or biopsies or blood or coexpress* or co-express* or conduction or “CT scan*” or cytokine or cytokines or diagnos* or dysfunction* or electromyograph* or endoscop* or fluid or fluids or fMRI or genet* or “gene expression” or imaging or inflammat* or marker or markers or MRI or “Magnetic resonance imaging” or mechanism* or neurodegenerat* or neuro-degenerat* or neuroendocrine or neuro-endocrine or neuroimag* or neuro-imag* or neuroinflammat* or neuro-inflammat* or protein or proteins or pulse or receptor or receptors or saliva or scan or scans or scanning or semen or serum or signal* or specimen* or temperature or test or tests or tissue* or tomograph* or ultrasound or urine or “vital signs” or x-ray*).ti,ab. (1453074)
7. or/5-6 (1453534)
8. and/4,7 (1097)
9. 8 not (“animal model” or “animal models” or cat or cats or dog or dogs or marmoset* or mice or mouse or pig or pigs or rat or rats or rodent or sheep or species or swine or bTBI or mTBI or sTBI or PTSD or TBI or “posttraumatic stress” or “post-traumatic stress” or “traumatic brain injury” or “traumatic brain injuries”).ti. (625)
10. limit 9 to english language (608)
11. limit 10 to yr="1990 -Current" (608)

## EBM Reviews - Cochrane Database of Systematic Reviews 2005 to February 21, 2020

Date searched: February 21, 2020

1. (“Desert Saber” or “Desert Sabre” or “Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Persian Gulf Syndrome” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab. (0)
2. (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab. (0)
3. ((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) and (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or Veteran*)).ti,ab. (0)
4. or/1-3 (0)
5. (antigen or antigens or autoantibod* or auto-antibod* or antibody or antibodies or bioassay* or bio-assay* or biological measure* or bio-marker* or biopsy or biopsies or blood or coexpress* or co-express* or conduction or “CT scan*” or cytokine or cytokines or diagnos* or dysfunction* or electromyograph* or endoscop* or fluid or fluids or fMRI or genet* or “gene expression” or imaging or inflammat* or marker or markers or MRI or “Magnetic resonance imaging” or mechanism* or neurodegenerat* or neuro-degenerat* or neuroendocrine or neuro-endocrine or neuroimag* or neuro-imag* or neuroinflammat* or neuro-inflammat* or protein or proteins or pulse or receptor or receptors or saliva or scan or scans or scanning or semen or serum or signal* or specimen* or temperature or test or tests or tissue* or tomograph* or ultrasound or urine or “vital signs” or x-ray*).ti,ab. (4210)
6. and/4-5 (0)

## EBM Reviews - Cochrane Central Register of Controlled Trials January 2020

Date searched: February 21, 2020

1. (“Desert Saber” or “Desert Sabre” or “Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Persian Gulf Syndrome” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab. (111)
2. (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab. (54)
3. ((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) and (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or Veteran*)).ti,ab. (257)
4. or/1-3 (356)
5. (antigen or antigens or autoantibod* or auto-antibod* or antibody or antibodies or bioassay* or bio-assay* or biological measure* or bio-marker* or biopsy or biopsies or blood or coexpress* or co-express* or conduction or “CT scan*” or cytokine or cytokines or diagnos* or dysfunction* or electromyograph* or endoscop* or fluid or fluids or fMRI or genet* or “gene expression” or imaging or inflammat* or marker or markers or MRI or “Magnetic resonance imaging” or mechanism* or neurodegenerat* or neuro-degenerat* or neuroendocrine or neuro-endocrine or neuroimag* or neuro-imag* or neuroinflammat* or neuro-inflammat* or protein or proteins or pulse or receptor or receptors or saliva or scan or scans or scanning or semen or serum or signal* or specimen* or temperature or test or tests or tissue* or tomograph* or ultrasound or urine or “vital signs” or x-ray*).ti,ab. (836972)
6. and/4-5 (197)
7. 6 not (“animal model” or “animal models” or cat or cats or dog or dogs or marmoset* or mice or mouse or pig or pigs or rat or rats or rodent or sheep or species or swine or bTBI or mTBI or sTBI or PTSD or TBI or “posttraumatic stress” or “post-traumatic stress” or “traumatic brain injury” or “traumatic brain injuries”).ti. (117)

## ClinicalTrials.gov

Date searched: February 21, 2020

( EXPAND[Concept] ( “Desert Saber” OR “Desert Sabre” OR “Desert Shield” OR “Desert Storm” OR “Gulf War” OR “Gulf Conflict” OR “Gulf Crisis” OR “Persian Gulf Syndrome” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY” OR “GWI” OR “GWIs” OR “GWVI” OR “GWVIs” ) OR AREA[ConditionSearch] ( Gulf AND ( illness OR syndrome ) ) ) | antigen OR autoantibody OR auto-antibody OR antibody OR bioassay OR bio-assay OR biological measure OR bio-marker OR biopsy OR blood OR coexpression OR co-expression OR conduction OR CT OR cytokine OR diagnosis OR diagnostic OR electromyography OR endoscopy OR fluid OR fMRI OR genetic OR gene OR imaging OR inflammation OR marker OR MRI OR magnetic OR mechanism OR neurodegeneration OR neuro-degeneration OR neuroendocrine OR neuro-endocrine OR neuroimaging OR neuro-imaging OR neuroinflammation OR neuro-inflammation OR protein OR pulse OR receptor OR saliva OR scan OR semen OR serum OR signaling OR specimen OR temperature OR test OR tissue OR tomography OR ultrasound OR urine OR vital or x-ray

(36)

## WHO ICTRP

Date searched: February 21, 2020

Condition = “Desert Saber” OR “Desert Sabre” OR “Desert Shield” OR “Desert Storm” OR “Gulf Conflict” OR “Gulf Crisis” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY” OR (Gulf AND (illness OR syndrome)) OR GWI OR GWIs OR GWVI OR GWVIs (Without synonyms checked)

Recruitment Status = ALL

(53)