# References

1 Donta ST, Engel CC, Jr., Collins JF, . Benefits and harms of doxycycline treatment for Gulf War veterans’ illnesses: a randomized, double-blind, placebo-controlled trial. Ann Intern Med. 2004;141(2):85–94.15262663
2 Golier JA, Caramanica K, Michaelides AC, . A randomized, double-blind, placebo-controlled, crossover trial of mifepristone in Gulf War veterans with chronic multisymptom illness. Psychoneuroendocrinology. 2016;64:22–30.26600007
3 Brewer Kl, Mainhart A, Meggs WJ. Double-blinded placebo-controlled cross-over pilot trial of naltrexone to treat Gulf War Illness. Fatigue: biomedicine, health and behavior. 2018;6(3):132.
4 Tuteja AK, Talley NJ, Stoddard GJ, Verne GN. Double-Blind Placebo-Controlled Study of Rifaximin and Lactulose Hydrogen Breath Test in Gulf War Veterans with Irritable Bowel Syndrome. Dig Dis Sci. 2019;64(3):838–845.30370492
5 Baraniuk JN, El-Amin S, Corey R, Rayhan R, Timbol C. Carnosine treatment for gulf war illness: a randomized controlled trial. Global Journal of Health Science. 2013;5(3):69–81.23618477
6 Golomb BA, Allison M, Koperski S, Koslik HJ, Devaraj S, Ritchie JB. Coenzyme Q10 benefits symptoms in Gulf War veterans: results of a randomized double-blind study. Neural Comput. 2014;26(11):2594–2651.25149705
7 Donta ST, Clauw DJ, Engel CC, Jr., . Cognitive behavioral therapy and aerobic exercise for Gulf War veterans’ illnesses: a randomized controlled trial. JAMA. 2003;289(11):1396–1404.12636462
8 Kerr K, Morse G, Graves D, Zuo F, Lipowicz A, Carpenter DO. A Detoxification Intervention for Gulf War Illness: A Pilot Randomized Controlled Trial. Int J Environ Res Public Health. 2019;16(21).
9 Kearney DJ, Simpson TL, Malte CA, Felleman B, Martinez ME, Hunt SC. Mindfulness-based Stress Reduction in Addition to Usual Care Is Associated with Improvements in Pain, Fatigue, and Cognitive Failures Among Veterans with Gulf War Illness. Am J Med. 2016;129(2):204–214.26519614
10 Nakamura Y, Lipschitz DL, Donaldson GW, . Investigating Clinical Benefits of a Novel Sleep-Focused Mind-Body Program on Gulf War Illness Symptoms: A Randomized Controlled Trial. Psychosom Med. 2017;79(6):706–718.28406803
11 Conboy L, Gerke T, Hsu KY, St John M, Goldstein M, Schnyer R. The Effectiveness of Individualized Acupuncture Protocols in the Treatment of Gulf War Illness: A Pragmatic Randomized Clinical Trial. PLoS ONE [Electronic Resource]. 2016;11(3):e0149161.
12 Amin MM, Gold MS, Broderick JE, Gold AR. The effect of nasal continuous positive airway pressure on the symptoms of Gulf War illness. Sleep & Breathing. 2011;15(3):579–587.20717848
13 Institute of Medicine. Gulf War and Health: Treatment for Chronic Multisymptom Illness. Washington, DC 2013.
14 Fukuda K, Nisenbaum R, Stewart G, . Chronic multisymptom illness affecting Air Force veterans of the Gulf War. JAMA. 1998;280(11):981–988.9749480
15 Steele L. Prevalence and patterns of Gulf War illness in Kansas veterans: association of symptoms with characteristics of person, place, and time of military service. Am J Epidemiol. 2000;152(10):992–1002.11092441
16 Institute of Medicine. Chronic Multisymptom Illness in Gulf War Veterans: Case Definitions Reexamined. National Academies Press (US) 2014;03(12).
17 Chester JE, Rowneki M, Van Doren W, Helmer DA. Progression of intervention-focused research for Gulf War illness. Mil Med Res. 2019;6(1):31.31627737
18 Department of Veterans Affairs (USA), Department of Defense (USA). VA/DoD clinical practice guideline for the management of chronic multisymptom illness. October 2014. https://www.healthquality.va.gov/guidelines/MR/cmi/VADoDCMICPG2014.pdf.
19 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–46.27005575
20 Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531
21 Berkman ND, Lohr KN, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. Methods Guide for Comparative Effectiveness Reviews (Prepared by the RTI-UNC Evidence-based Practice Center under Contract No. 2902007–10056-I). AHRQ Publication No. 13(14)-EHC130-EF. Rockville, MD: Agency for Healthcare Research and Quality. November 2013. www.effectivehealthcare.ahrq.gov/reports/final.cfm.
22 Atkins D, Chang SM, Gartlehner G, . Assessing applicability when comparing medical interventions: AHRQ and the Effective Health Care Program. J Clin Epidemiol. 2011;64(11):1198–1207.21463926
23 rTMS for the Treatment of Chronic Pain in GW1 Veterans. ClinicalTrials.gov identifier NCT01608321. https://ClinicalTrials.gov/show/NCT01608321. Accessed 14 November 2019.
24 Research Examining Gulf War Illness in Our Nations Service Members. ClinicalTrials.gov identifier NCT01846182. https://clinicaltrials.gov/show/NCT01846182.
25 Brandley E, Kirkland A, Sarlo G, VanMeter J, Baraniuk J, Holton K. The Effects of a Low Glutamate Dietary Intervention on Anxiety and PTSD in Veterans with Gulf War Illness (FS15–08-19). Current Developments in Nutrition. 2019;3(Suppl 1).
26 Cognitive Behavioral Therapy for Insomnia for Gulf War Illness. ClinicalTrials.gov identifier NCT02782780. https://clinicaltrials.gov/show/NCT02782780. Accessed 14 November 2019.
27 Cognitive Rehabilitation for Gulf War Illness. ClinicalTrials.gov identifier NCT02161133. https://clinicaltrials.gov/show/NCT02161133. Accessed 14 November 2019.
28 Groups for Regaining Our Wellbeing. ClinicalTrials.gov identifier NCT03058952. https://clinicaltrials.gov/show/NCT03058952. Accessed 14 November 2019.
29 Engel CC, Jr., Liu X, Clymer R, Miller RF, Sjoberg T, Shapiro JR. Rehabilitative care of war-related health concerns. J Occup Environ Med. 2000;42(4):385–390.10774507
30 Treatment of Memory Disorders in Gulf War Illness With High Definition Transcranial Direct Cortical Stimulation. ClinicalTrials.gov identifier NCT03542383. https://clinicaltrials.gov/show/NCT03542383. Accessed 14 November 2019.
31 Alleviating Headache and Pain in GWI With Neuronavigation Guided rTMS. ClinicalTrials.gov identifier NCT03030794. https://www.clinicaltrials.gov/ct2/show/study/NCT03030794. Accessed 14 November 2019.
32 rTMS in Alleviating Pain and Co-Morbid Symptoms in Gulf War Veterans Illness (GWVI). ClinicalTrials.gov identifier NCT04046536. https://ClinicalTrials.gov/show/NCT04046536. Accessed 14 November 2019.
33 Long Term Efficacy of Neuronavigation Guided rTMS in Alleviating Gulf War Illness Related Headaches and Pain Symptoms. identifier NCT04182659. https://ClinicalTrials.gov/show/NCT04182659. Accessed October 1.
34 Transcranial Direct Current Stimulation for Pain Treatment in Gulf War Illness. ClinicalTrials.gov identifier NCT03547869. https://clinicaltrials.gov/show/NCT03547869. Accessed 14 November 2019.
35 Vagus Nerve Stimulation: Treatment for Gulf Veterans With Gulf War Illness. ClinicalTrials.gov identifier NCT02791893. https://clinicaltrials.gov/show/NCT02791893. Accessed 14 November 2019.
36 Acupressure for Pain Management and Fatigue Relief in Gulf War Veterans. ClinicalTrials.gov identifier NCT02075489. https://clinicaltrials.gov/show/NCT02075489. Accessed 14 November 2019.
37 CAM in Veterans With Gulf War Illnesses. ClinicalTrials.gov identifier NCT02180243. https://clinicaltrials.gov/show/NCT02180243. Accessed 14 November 2019.
38 Novel Interventions for GWVI. ClinicalTrials.gov identifier NCT02661997. https://clinicaltrials.gov/show/NCT02661997. Accessed 14 November 2019.
39 Treating Chronic Pain in Gulf War Illness. ClinicalTrials.gov identifier NCT02378025. https://clinicaltrials.gov/show/NCT02378025. Accessed 14 November 2019.
40 Effect of Diet on Gulf War Illness. ClinicalTrials.gov identifier NCT02881944. https://clinicaltrials.gov/show/NCT02881944. Accessed 14 November 2019.
41 Glutamate Neuro-Excitotoxicity in GWI. ClinicalTrials.gov identifier NCT03342482. https://ClinicalTrials.gov/show/NCT03342482. Accessed 14 November 2019.
42 Holton K. Glutamate Neuroexcitotoxicity in GWI. Department of Defense - Congressionally Directed Medical Research Programs. https://cdmrp.army.mil/search.aspx?LOG_NO=GW160118. Accessed.
43 Impact of Exercise Training on Pain and Brain Function in Gulf War Veterans. ClinicalTrials.gov identifier NCT01350492. https://clinicaltrials.gov/show/NCT01350492. Accessed 14 November 2019.
44 D-cycloserine: A Novel Treatment for Gulf War Illness (GWDCS). ClinicalTrials.gov identifier NCT02983734. https://clinicaltrials.gov/show/NCT02983734. Accessed 14 November 2019.
45 NCT04254627. Tumor Necrosis Factor (TNF) and Glucocorticoid Antagonist for Gulf War Illness (GWI)-Associated Multi-symptom Disease Homeostasis Reset. In. Nova Southeastern University Y, International RTI, Rochester General H, trans 2020.
46 Intranasal Insulin: A Novel Treatment for Gulf War Multisymptom Illness. ClinicalTrials.gov identifier NCT01802944. https://clinicaltrials.gov/show/NCT01802944. Accessed 14 November 2019.
47 Gulf War Illness Inflammation Reduction Trial. ClinicalTrials.gov identifier NCT02506192. https://clinicaltrials.gov/show/NCT02506192. Accessed 14 November 2019.
48 Complementary Neurosteroid Intervention in Gulf War Illnesses (GWVI). ClinicalTrials.gov identifier NCT01956279. https://clinicaltrials.gov/show/NCT01956279. Accessed 14 November 2019.
49 Klimas N. The Use of B-Cell Depletion Therapy (BCDT) in Gulf War Illness: A Phase 1/2 Study. Department of Defense - Congressionally Directed Medical Research Programs Web site. https://cdmrp.army.mil/search.aspx?LOG_NO=GW160123. Accessed.
50 Holodniy M, Kaiser JD. Treatment for Gulf War Illness (GWI) with KPAX002 (methylphenidate hydrochloride + GWI nutrient formula) in subjects meeting the Kansas case definition: A prospective, open-label trial. J Psychiatr Res. 2019;118:14–20.31446218
51 Effects of Botanical Microglia Modulators in Gulf War Illness. ClinicalTrials.gov identifier NCT02909686. https://clinicaltrials.gov/show/NCT02909686. Accessed 14 November 2019.
52 Development of a Polyphenol-rich Dietary Preparation for Treating Veterans With Gulf War Illness. ClinicalTrials.gov identifier NCT02915237. https://clinicaltrials.gov/show/NCT02915237. Accessed 14 November 2019.
53 Mitochondrial Cocktail for Gulf War Illness. ClinicalTrials.gov identifier NCT02804828. https://www.clinicaltrials.gov/ct2/show/NCT02804828. Accessed 14 November 2019.
54 Multimodal Investigation of the Neuroprotective Effects of Resveratrol (MINER). ClinicalTrials.gov identifier NCT03665740. https://clinicaltrials.gov/show/NCT03665740. Accessed 14 November 2019.
55 CoQ10 in Gulf War Illness. ClinicalTrials.gov identifier NCT02865460. https://clinicaltrials.gov/show/NCT02865460. Accessed 14 November 2019.
56 Probiotic (Visbiome) for Gulf War Illness. ClinicalTrials.gov identifier NCT03078530. https://clinicaltrials.gov/show/NCT03078530. Accessed 14 November 2019.
57 Serrador JM, Schubert MC, Brewer K, Breen P, Wood SJ. Gulf War Illness is associated with reduced vestibular function that can be restored using a novel imperceptible GVS neuromodulation device based on stochastic resonance. Neuroscience; November 7, 2018.
58 Scalp Application of Red and Near-Infrared Light, From Light-Emitting Diodes (LED) to Improve Thinking and Memory in Veterans With Gulf War Illnesses. ClinicalTrials.gov identifier NCT01782378. https://clinicaltrials.gov/show/NCT01782378. Accessed 14 November 2019.
59 Hayer SD, Rabago DP, Amaza IP, . Effectiveness of nasal irrigation for chronic rhinosinusitis and fatigue in patients with Gulf War illness: protocol for a randomized controlled trial. Contemp Clin Trials. 2015;41:219–226.25625809
60 Gulf War Illness Nasal Irrigation Study. ClinicalTrials.gov identifier NCT01700725. https://clinicaltrials.gov/show/NCT01700725.
61 Bayley, P. J., Cho, R. Schulz-Heik, R. J., Mathersul, D. C., Collery L., Shankar, K. Ashford, J. W. Jennings, J. Tang, J. Wong, M. Avery, T. J. Stanton, M. Meyer, H. Friedman, M. Kim, S. Jo, B. Younger, J. Mathews B., Majmundar M. & Mahoney L. Yoga is effective in treating symptoms of gulf war illness: a randomized clinical trial (in review).
62 Bayley PJ. Comparative Efficacy of Yoga vs. Cognitive Behavioral Therapy (CBT) For Treating Chronic Pain in Gulf War Illness: Preliminary Findings. Meeting of the Research Advisory Committee on Gulf War Veterans’ Illnesses; 2018.
63 McNeil RB, Thomas CM, Coughlin SS, . An assessment of survey measures used across key epidemiologic studies of United States Gulf War I Era veterans. Environ Health. 2013;12:4.23302181
64 Program DCDMR. GWI Common Data Elements Initiative. https://cdmrp.army.mil/GWIRP/research_highlights/19gwi_cde_initiative_highlight.aspx. Published 2019. Updated 22 January 2019. Accessed 10 April 2020.
65 Veterans Affairs/Department of Defense. Gulf War Illness Common Data Elements Project: Draft Version 1.0. 2018.
66 McPheeters M, Butler M, Maglione M, . AHRQ Methods for Effective Health Care. Challenges in Conducting EPC Reviews of Behavior Change Interventions. 2015.
67 Hrobjartsson A, Emanuelsson F, Skou Thomsen AS, Hilden J, Brorson S. Bias due to lack of patient blinding in clinical trials. A systematic review of trials randomizing patients to blind and nonblind sub-studies. Int J Epidemiol. 2014;43(4):1272–1283.24881045
68 Milling LS, Reardon JM, Carosella GM. Mediation and moderation of psychological pain treatments: response expectancies and hypnotic suggestibility. J Consult Clin Psychol. 2006;74(2):253–262.16649870
69 Department of Defense - Congressionally Directed Medical Research Program. Gulf War Illness: Research Resources Initiative by the GWIRP: Clinical Interventions. https://cdmrp.army.mil/gwirp/resources/cinterventions. Published 2018. Accessed 18 February 2020.
70 DoD Congressionally Directed Medical Research Programs. Use of a Portable Stimulator to Treat GWI. https://cdmrp.army.mil/search.aspx?LOG_NO=GW130093. Accessed 6 April 2020.