# Acknowledgments

This topic was developed in response to a nomination by Karen Block, PhD, Director of Gulf War Research in the Veterans Affairs (VA) Office of Research and Development (ORD) Gulf War Research Program, for the purpose of informing the planning for a state-of-the-art meeting on Gulf War Research and providing guidance for ORD funding priorities in Gulf War research. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the Technical Expert Panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Robin Paynter, MLIS, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Karen Block, PhD
  Office of Research and Development (ORD) (10P9) – Gulf War Research Program
  Washington, DC
- Drew Helmer, MD, MS
  Deputy Director, Center for Innovations in Quality, Effectiveness and Safety (IQuESt)
  Houston, TX

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Peter Rumm, MD, MPH, FACPM
  Pre-9/11 Era-Program Post-Deployment Health Services
  Washington, DC
- Matthew Reinhard, PsyD
  DC War Related Illness and Injury Study Center
  Washington, DC
- Lisa McAndrew, PhD
  NJ War Related Illness and Injury Study Center
  East Orange, NJ
- Francis (Fran) Murphy, MD, MPH
  Sigma Health Consulting
  Washington, DC area
- Peter Bayley, PhD
  CA War Related Illness and Injury Study Center
  Palo Alto, CA
- Rebekah (Ryanne) Wu, MD, MHS
  Durham VA Health Care System
  Durham, NC
- Stephen C. Hunt, MD, MPH
  VA Puget Sound Health Care System
  Seattle, WA
- Eva Lee, PhD
  Georgia Institute of Technology
  Atlanta, GA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.