# Conclusions

We found a small but growing body of evidence examining a disparate array of treatments for Veterans with GWI (see Summary Table). There is low- to moderate-strength evidence that suggests several treatments may hold promise for improving symptoms related to GWI. The evidence was moderate-strength for benefits of a combination of CBT and exercise and low-strength for 2 distinct mindfulness-based interventions and CPAP for Veterans with GWI who have sleep-disordered breathing. Doxycycline, on the other hand, is likely to be an ineffective treatment and is associated with harms (moderate-strength evidence). There are 33 ongoing, single-arm pilot, or unpublished studies examining a variety of interventions; some of these studies will help strengthen the evidence base for interventions that have already been examined on a small scale (eg, CBT and mindfulness-based stress reduction). However, many of these studies examine interventions that are both different from each other and different from interventions that have been studied before. While this approach may help identify potentially promising interventions, the variety of treatments examined will make it challenging to develop enough of an evidence base to guide clinicians about which treatments are most likely to be effective in clinical practice and which treatments should be avoided. Part of the challenge in studying treatment of GWI is the lack of an agreed-upon case definition, and the heterogeneity of symptoms and differing degrees of functional impairment experienced by those with GWI. Addressing these issues will help researchers to better target intervention-focused research.

Summary Table Visual representation of findings

Treatment; Subpopulation if applicable | Outcome domain
Treatment; Subpopulation if applicable | Physical health overall | Pain | Cognitive | Fatigue | Mental health overall | Depression | Global outcomes (function, QoL) | PTSD symptoms | Sleep | GI symptoms | Adverse events
Medications vs placebo
Doxycycline^1^; Positive mycoplasma | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | ★★
Mifepristone^2^ | Ø | --- | Ø | Ø | Ø | Ø | --- | Ø | --- | --- | Ø
Naltrexone^3^ | Ø | --- | Ø | --- | --- | --- | --- | --- | --- | --- | Ø
Rifaximin^4^; IBS (Rome III) | --- | --- | --- | --- | --- | --- | Ø | --- | --- | Ø | Ø
Nutritional supplements vs placebo
Carnosine^5^ | --- | Ø | Ø | Ø | --- | --- | --- | --- | --- | Ø | Ø
CoQ10^6^ | Ø | --- | Ø | --- | --- | --- | --- | --- | --- | --- | Ø
Psychological, exercise, or multi-component interventions
CBT^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
Exercise^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
CBT + Exercise in combination^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
Detox regimen^b^,^8^ | Ø | Ø | --- | Ø | Ø | --- | Ø | --- | --- | --- | Ø
Mindfulness-based stress reduction^b^,^9^ | --- | ★ | ★ | ★ | --- | ★ | --- | ★ | --- | --- | ---
Sleep focused mind-body bridging^c^,^10^ | Ø | Ø | Ø | ★ | Ø | ★ | Ø | ★ | ★ | --- | ---
Other interventions
Acupuncture^a^,^11^ | Ø | Ø | --- | --- | --- | --- | --- | --- | --- | --- | Ø
CPAP^d^,^12^ | ★ | ★ | ★ | ★ | ★ | --- | --- | --- | ★ | --- | ---

Shading represents the direction of effect: Pale yellow=Mixed Findings/Unclear, Green=Evidence of benefit, Gray=No association, Red=Favors usual care

Symbols represent the strength of the evidence: --- No evidence, Ø Insufficient, ★Low, ★★ Moderate, ★★★ High

a Versus usual care/TAU

b Versus waitlist

c Versus sleep education

d Versus sham CPAP