# Discussion

We conducted a comprehensive review of treatments for GWI and found studies of several interventions that reported improvements in various GWI symptom domains. A large multi-arm study of CBT and exercise found moderate-strength evidence of benefit with CBT and exercise alone and in combination.^7^ Studies of mindfulness-based interventions (MBB and MBSR) also found low-strength evidence of improvement on several outcome measures.^9,10^ CPAP improved overall physical health, pain, cognitive functioning, fatigue, mental health, and sleep quality in participants with GWI and sleep-disordered breathing (low SOE).^12^ Studies of nutritional supplements^5,6^ and acupuncture^11^ showed some indications of benefit, though the evidence was insufficient due to methodological issues (Appendix C). Several interventions were found to have no treatment effect, including doxycycline, mifepristone, and naltrexone.

Several trials found promising effects on some outcomes but no treatment effects on other outcome measures. Among the interventions, it is important to also consider potential for harms. Adverse events occurred more frequently with 2 interventions: doxycycline^1^ and a detoxification and sauna regimen.^8^ It is unclear whether the psychosocial and exercise interventions are associated with increased risk of adverse events. This will be important information to ascertain with greater certainty in future, larger trials.

Among the ongoing studies, there appears to be emerging interest in central nervous system (CNS) stimulation therapies and complementary and integrative health (CIH) approaches for treating GWI. Medications and nutritional supplements continue to be evaluated, although no particular medication has been studied in more than 1 trial in either KQ1 or KQ3. Figure 3 shows the types of interventions examined among the 12 published RCTs in KQ1 and the 32 ongoing/unpublished/single-arm studies in KQ3.

Figure 3 Frequency of intervention categories^*^ * Because 1 study had 3 active treatment arms,^7^ there are 47 intervention arms represented among 45 total studies. Abbreviations: CNS=Central Nervous System; KQ=Key Question. among published (KQ1) and unpublished (KQ3) studies of treatments for GWI

It has been almost 7 years since the Institute of Medicine’s (IOM) Committee on Gulf War and Health: Treatment for Chronic Multisymptom Illness’ review, which also included studies in non-Veterans and treatments for conditions and comorbidities other than GWI (eg, fibromyalgia, IBS, depression, etc.). The IOM report did not conclusively recommend any interventions but advised that antidepressant medications (SSRIs and SNRIs) as well as CBT may be helpful for some. Authors of the report also emphasized that this is a complex illness and individualized health care management plans are necessary. More recently, a narrative review of intervention-focused GWI research was published in 2019,^17^ which included 7 studies that also met our inclusion criteria for this review. We have added to the findings of that 2019 review by performing a critical appraisal of the 7 included studies and identifying 5 additional treatment studies. We further conducted a comprehensive search for VA- and DoD-funded studies and found many studies that are ongoing or completed but unpublished. The expanded scope of this review helps to characterize what is currently known about GWI interventions, and to inform future directions for GWI research.

## Limitations

There are several limitations that should be considered, both of our review, as well as of the body of literature that we reviewed. Regarding our review, we were not able to combine results into a meta-analysis due to the heterogeneity of outcomes and interventions assessed.

With regard to the body of literature, there are several limitations to this evidence base. The absence of participant blinding was a frequent limitation, particularly among the psychosocial interventions, which results in potential bias for self-reported outcomes. The magnitude of treatment effect was not always reported, and documentation of adverse events was inconsistent among the trials. Of all the GWI treatment studies we reviewed, only 2 are low ROB (Doxycycline^1^ and CPAP^12^) and 1 of them had a very small sample size (CPAP, N=18).^12^ Moreover, while CPAP is an evidence-based treatment for sleep apnea, it was also associated with improvement on a broader range of GWI symptom in this study, not just sleep outcomes, so it is important to include.

### Heterogeneity

Heterogeneity among the interventions, outcome measures, and other study characteristics limited our ability to draw conclusions. Because we identified only 1 study each of the 12 different interventions included in KQ1, we were unable to conduct meta-analyses.

There are many methodologic challenges in studying treatments for GWI all of which drive the issues of heterogeneity. These include variation in case definition, lack of common and disease-specific outcome measures for GWI, as well as differing interpretations of the pathophysiology of GWI itself. With regard to variation in case definitions, it is a major challenge to develop an evidence base for treating an illness that does not yet have an agreed upon set of symptoms, clinical presentation or measurement tools.^63^ While there is overlap in some of the symptoms required to meet either the CDC or Kansas case definitions, individuals with GWI often present with wide range and variability in their symptoms, potentially resulting in too heterogeneous of a sample to see a treatment effect. Luckily 2 ongoing studies both leveraging VA administrative data (one employing a comprehensive chart review; PI: Helmer) and the other is employing a machine learning approach to identify health care data clusters that are associated with GWI (PI: Dursa), both will provide additional clarity on a case definition. Finally, there is a range of illness severity that is not well captured by the current measurement of GWI and not consistently measured and/or reported across the studies. Lack of a standard measure of global GWI symptoms and symptom clusters to measure a potential global reduction also resulted in a high degree of heterogeneity in outcome measures across studies (can cite McNeil 2013 again here). To try and address this challenge, in 2018, the Gulf War Illness Common Data Elements Symptoms Work Group^64^ developed a recommendation for the battery of measures to be used to assess symptom frequency, severity, and functional impairment.^65^ Ideally, moving forward, trials could use these recommended measures in order to combine results into larger meta-data from which to draw stronger conclusions about effectiveness of treatments.

A common limitation of the psychosocial and exercise intervention literatures was the use of self-reported outcomes accompanied with a lack of participant blinding. The role and necessity of patient blinding in studies of these types of interventions has been debated. There are techniques even for complex nonpharmacologic interventions to blind patients to some degree.^66^

Some argue that lack of patient blinding in trials of non-pharmacologic therapies may considerably exaggerate treatment effects.^67^ In which case, it would be difficult to determine whether and to what extent positive treatment effects – especially for the findings with only low level confidence – were due to an independent effect of treatment, expectancy as a mechanism of change, placebo effect, or a combination of these factors. On the other hand, others have argued that blinding is not only challenging but also potentially counterproductive as expectancy for change is thought to be an integral part of the intervention itself.^68^

### Publication Bias

For KQ3, we identified lists of funded trials from the DoD^69^ and VA and searched for publications based on these funded trials. We found 31 studies that have not been published. Results of 3 of these studies have been posted publicly. No findings have been posted for 5 studies, of which 2 were completed in 2017, and 2 in 2018. The absence of published findings from completed studies suggests the potential for publication bias or other barrier to publication.

### Applicability of Findings to the VA Population

All of these studies were conducted in Veteran participants with GWI, and many of the studies that showed effectiveness were conducted in a VA setting, so there is a high degree of applicability to Veterans who receive care at the VA. Also, some of the studies include important subpopulations (eg, those with sleep-disordered breathing, PTSD, or IBS). Yet, there may be less applicability to Veterans who do not receive care in the VA or who do not have access to specialty medical, post-deployment, or mental health care.

## Implications for VHA

The findings of this report can help to inform priorities for future funding and clinical inquiry. There are several promising interventions including mindfulness-based approaches, CBT and exercise (separately or together), and the use of a CPAP among those with sleep-disordered breathing and GWI. The VA is in a unique position to offer integrated specialty and mental health care, which may be the ideal care model to effectively manage those with GWI.

## Research Gaps/Future Research

There are many areas of future inquiry that should be considered. Several potentially promising interventions that have demonstrated effectiveness to improve 1 or more symptoms include: mindfulness-based approaches, CBT and exercise (separate or together), and the use of a CPAP among those with GWI who have sleep-disordered breathing. The implementation of these in VA should be studied. We identified a broader literature of ongoing or single-arm studies from which we could not draw conclusions, but which may point us in the direction of promising novel therapies. Notable among these was a Specialized Care Program, and dietary interventions (low-glutamate diet; nutrient formula combined with methylphenidate), which warrant further investigation and movement to effectiveness trials.

In the context of an aging population of Gulf War Era Veterans, especially those with GWI, symptoms may be exacerbated either by the aging process or by the development of other medical comorbidities. Interventions with low risk of adverse effects are an important consideration. Studies examining GWI sub-populations were quite limited. Only 3 trials examined effects on Veterans with GWI who also had a specific comorbidity (1 each of IBS, PTSD, and sleep-disordered breathing), leaving many subpopulations in need of future research.

In sum, research gaps and future ways to improve the evidence base include:

(1) Consolidation of intervention work, replicating promising interventions and conducting studies of a hybrid design to assess effectiveness and feasibility of implementation of promising interventions in VA settings;
(2) Development of a single case definition that considers the onset of other chronic health conditions in this aging population;
(3) Development and use of consistent outcome measures capable of assessing the depth and breadth of GWI symptoms, considering the severity of illness to differentiate those with severe and less severe disease, and measuring longitudinal change in symptom severity.