# Results

We reviewed a total of 4,621 citations. After title and abstract review, 155 met inclusion criteria. After we reviewed the full text of these studies, we included a total of 45 studies. A diagram of the literature yield is shown in Figure 2.

Figure 2 Literature Flow Chart

Abbreviations: CCRCT=Cochrane Central Register of Controlled Trials; CDSR=Cochrane Database of Systematic Reviews; CINAHL=Cumulative Index to Nursing and Allied Health Literature; EBM=Evidence-based Medicine; KQ= Key Question; RCT=Randomized Controlled Trial; WHO=World Health Organization

Twelve RCTs addressed KQ1. The interventions included 4 medications (doxycycline,^1^ mifepristone,^2^ naltrexone,^3^ and rifaximin^4^); 2 nutritional supplements (carnosine^5^ and CoQ10^6^); 4 studies with a behavioral or psychological treatment component (cognitive behavioral therapy [CBT] with and without exercise,^7^ a detox regimen,^8^ and 2 mindfulness-based interventions^9,10^); acupuncture^11^; and continuous positive airway pressure therapy (CPAP).^12^

Four interventions were examined in specific subpopulations of GWI patients: doxycycline in patients positive for mycoplasma DNA,^1^ rifaximin in patients with irritable bowel syndrome (IBS),^4^ mind-body bridging (MBB) in patients with sleep disturbance,^10^ and CPAP in patients with sleep-disordered breathing.^12^ In a study of mindfulness-based stress reduction (MBSR), patients diagnosed with posttraumatic stress disorder (PTSD) made up a large proportion (81.8%) of the sample, and the effect of the intervention on PTSD symptoms was evaluated specifically in this subgroup.^9^

Although the findings of these studies may be most applicable to the targeted subpopulations, none of the studies identified in our search addressed KQ2 by comparing the effects of an intervention in the subpopulation with a broader sample of GWI patients. Additionally, although considered eligible in our selection criteria, our search did not yield any cohort studies that addressed the key questions.

For KQ3, we compiled information from 31 intervention studies that are ongoing or unpublished, as well as 2 published single-arm intervention studies. In describing the current research on interventions, we also included 2 studies that were terminated before completion^23,24^ due to low enrollment or for unspecified reasons.

The findings for each KQ are presented in the sections that follow.

## KEY QUESTION 1 What are the benefits and harms of pharmacological and non-pharmacological interventions and management strategies for Veterans with GWI?

Table 2 provides descriptive characteristics about each of the 12 trials that addressed KQ1, including the interventions and comparators used, the duration of treatment, the duration of observation (which includes the treatment period), the populations studied, and the outcomes reported.

The outcomes measured varied among the studies (Table 2). Measures of physical health, pain, and cognitive function were reported most frequently. None of the included studies reported outcomes specifically for respiratory, dermatological, or musculoskeletal symptoms measured separately from overall pain.

Most of the studies used the CDC or Kansas criteria for defining GWI. Some studies used equivalent criteria or modified the CDC or Kansas criteria. One study of rifaximin^4^ included Gulf War Veterans with IBS.

Following Table 2, we provide a summary of the findings for each intervention, organized into 4 categories: medications, nutritional supplements, behavioral/exercise/multicomponent, and other interventions. Detailed findings on effectiveness and adverse events are provided in Appendix D, Tables 9–12.

Table 2 Characteristics of randomized controlled trials of interventions for Gulf War Illness

Study; Design; Setting; Years of enrollment; N=total participants; Overall ROB | Intervention vs comparator; Dose; N randomized Tx vs C; Duration of treatment and observation (includes treatment period) | Population; GWI case definition; Subpopulation, if applicable; Age: Mean (SD); Female: %; Race: % White/Afr Am/Other; Hispanic: %; Employed full-time: %; Clinical characteristics | Outcomes reported^a^
Study; Design; Setting; Years of enrollment; N=total participants; Overall ROB | Intervention vs comparator; Dose; N randomized Tx vs C; Duration of treatment and observation (includes treatment period) | Population; GWI case definition; Subpopulation, if applicable; Age: Mean (SD); Female: %; Race: % White/Afr Am/Other; Hispanic: %; Employed full-time: %; Clinical characteristics | Physical health overall | Pain | Cognitive | Fatigue | Mental health overall | Depression | Global outcomes^b^ | PTSD symptoms | Sleep | GI symptoms | Adverse events
Medications
Doxycycline ^1^; DB-RCT; Multisite: 26 VA and 2 DoD medical centers; Years: April 1999–Nov 2001; N=491; ROB: Low | Doxycycline 200 mg/day vs placebo; N=245 vs 246; Tx duration: 12 months; Observation: 18 months | CDC criteria; Subpop: mycoplasma DNA positive; Tx group only:; Age: 41.1 (9.2); Female: 15.5; Race: 61.6 / 26.5 / 7.8; Hispanic: NR; Employed: 73.5 | ✕ | ✕ | ✕ | ✕ | ✕ | --- | --- | --- | --- | --- | ✕
Mifepristone ^2^; DB-RCT, crossover; Single site, VA hospital 2008–2011; N=36; ROB: Some concerns | Mifepristone 200 mg/day vs placebo; Two, 3-week crossover Tx phases with 1-month washout; N=18 vs 18 in phase 1; 18 vs 15 in phase 2; Tx duration: 6 weeks; Observation: 4 months | Kansas criteria; Age: 49.1 (7.2); Female: 0.0; Race: 40.6 / 50.0 / 9.4; Hispanic: 50.0; Employed: 56.3 | ✕ | --- | ✕ | ✕ | ✕ | ✕ | --- | ✕ | --- | --- | ✕
Naltrexone ^3^; RCT, Pts blinded; Setting: NR; Years: NR; N=40; ROB: High | Naltrexone 4.5 mg/day vs placebo; 3-month crossover Tx phases separated by 1-month washout.; N=37 (completed both phases); Tx duration: 3 months; Observation: 7 months | Kansas, modified; Age: 54 (SD NR); Female: 2.7 (completed study); Race: NR; Employed: NR | ✕ | --- | ✕ | --- | --- | --- | --- | --- | --- | --- | ✕
Rifaximin ^4^; DB-RCT; Setting: NR; Years: NR; N=50; ROB: Some concerns | Rifaximin (550 mg 2x/d) vs placebo; N=27 vs 23; Tx duration: 2 weeks; Observation: 2 weeks | GWI criteria: NR; Subpopulation: IBS (Rome III); Tx group only:; Age, median: 53; Female: 13.6; Race: NR; Employed: NR | --- | --- | --- | --- | --- | --- | ✕ | --- | --- | ✕ | ✕
Nutritional supplements
Carnosine ^5^; DB-RCT; Single site: Georgetown Univ Hospital; 2008–2011; N=34; ROB: High | L-carnosine (dose of 500, 1,000, 1,500 mg/d increasing at 4-week intervals) vs placebo; N=34 (only 12 vs 13 finished study); Tx duration: 12 weeks; Observation: 14 weeks | CDC criteria, or GW Vet diagnosed with post-GW CFS; Of 25 study completers:; Age: 49.4; Female: 32; Race: NR; Employed: NR | --- | ✕ | ✕ | ✕ | --- | --- | --- | --- | --- | ✕ | ✕
CoQ10 ^6^; DB-RCT; Setting: Southern California Hospital; Years: NR; N=46; ROB: High | CoQ10 (2 dosage arms, 100 mg/day vs 300 mg/day) vs placebo; N=11 vs 12 vs 23; Tx duration: 3.5 +/− 0.5 months; Observation: 3.5 +/− 0.5 months | Required both CDC & Kansas criteria; Placebo vs Q100 vs Q300:; Age: 48 vs 50 vs 44; Female: 9 vs 27 vs 17; White: 55 vs 73 vs 58; Latino: 18 vs 0 vs 17; Afr Am: 9.1 vs 9.1 vs 25; Employed: NR | ✕ | --- | ✕ | --- | --- | --- | --- | --- | --- | --- | ✕
Psychological, exercise, or multi-component interventions
CBT + Exercise ^7^; 2x2 factorial RCT, Pts not blinded; Multi-site: 18 VAs and 2 DoD medical centers; April 1999–September 2001; N=1092; ROB: Some concerns | 4 arms:; CBT+Exercise (n=266); CBT only (n=286); Exercise only (n=265); TAU (n=270); Exercise sessions were 60 minutes and CBT sessions were 60 to 90 minutes; Each type of session held 1x/week.; Tx duration: 12 weeks; Observation: 12 months | CDC equivalent; Age: 40.67; Female: 14.8; Race: 52.5 / 24.4 / 3.4; Hispanic: 19.6; Employed: NR | ✕ | ✕ | ✕ | ✕ | ✕ | --- | --- | --- | --- | --- | ✕
Detox regimen ^8^; RCT, Pts not blinded; Commercial rehab center; 2013–2015; N=32; ROB: Some concerns | Detox regimen: niacin immediate release (dose NR); then 20–30 min moderate aerobic exercise; then low temperature sauna (60–80 Celsius) 2–4 hours; other vitamin/mineral supplements in calcium-magnesium drink throughout; vs waitlist; N=22 vs 10; Tx duration: 4–6 weeks; Observation: 3 months | Kansas criteria; Sex: 66% Male, 34% Female; Age: 51 (6.5); Race: 81 / 19 / 3; Hispanic: NR; Employed: 59 | ✕ | ✕ | --- | ✕ | ✕ | --- | ✕ | --- | --- | --- | ✕
Mindfulness-based stress reduction ^9^; RCT, Pts not blinded; Setting: VA Hospital; Years: NR; N=55; ROB: Some concerns | MBSR: 2.5 sessions 1x/week for 8 weeks + single 7-hour weekend session vs TAU; N=26 vs 29; Tx duration: 8 weeks; Observation: 6 months | CDC criteria; Subpopulation: PTSD 81.8%; ≥50% service-connected disability 79.6%; Age: 49.9; Female: 14.5; Race: 61.8 / 18.2 / 14.5; Hispanic: NR; Employed: NR | --- | ✕ | ✕ | ✕ | --- | ✕ | --- | ✕ | --- | --- | ---
Sleep-focused Mind-Body Bridging ^10^; Study design: Prospective RCT; Single site: VA Salt Lake City; 2012–2015; N=60; ROB: Some concerns | Sleep-focused MBB vs sleep education (SED; lectures, group discussions); N=33 vs 27; Tx duration: 3 sessions over 3 weeks; Observation: 3 months; Pts could remain on previously prescribed sleep medications. | CDC equivalent; Subpopulation: sleep disturbance; Age: 50.7; Female: 10.0; Race: 88.0 / 7.0 / 8.6; Hispanic: 8.3; Employed: NR | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | --- | ---
Other interventions
Acupuncture ^11^; RCT, Pts not blinded; 30 treatment sites; Enrolled 2010–2013; N=104; ROB: Some concerns | Acupuncture 2x/week for 6 months vs waitlist 2 months, then acupuncture; 1x/week for 4 months; N=52 vs 52; Tx duration: 6 months; Observation: 6 months | CDC criteria; Age: 48.2; Female: 13.0; Race: 80.7 / 9.6 / 9.6; Hispanic: 5.8; Employed: NR | ✕ | ✕ | --- | --- | --- | --- | --- | --- | --- | --- | ✕
CPAP ^12^; RCT, Pts blinded; Single site, VA hospital.; January 2006–July 2008; N=18; ROB: Low | Active nasal CPAP (using individualized pressure level that eliminated inspiratory airflow limitation) vs sham CPAP (pressure below 1 cm H_2_0); N=9 vs 9; Tx duration: 5+ hours/ night for 3 weeks; Observation: 3 weeks | Kansas equivalent; Subpopulation: sleep-disordered breathing; Age: 42 (4); Female/Race/Employed: NR; Apnea Hypopnea Index: 19 (25); Respiratory event-related arousal: 15 (10); Ptherapeutic (parallel level of nasal CPAP that eliminates inspiratory airflow limitation): 9 (2) cmH_2_O | ✕ | ✕ | ✕ | ✕ | ✕ | --- | --- | --- | ✕ | --- | ---
Total studies reporting outcome | | | 9 | 9 | 9 | 8 | 7 | 4 | 4 | 3 | 2 | 2 | 9

a No outcomes were reported for musculoskeletal, respiratory, or dermatological symptoms.

b Include measures of functional status and quality of life.

Abbreviations: CBT=Cognitive Behavioral Therapy; CDC=Centers for Disease Control and Prevention; CFS=Chronic Fatigue Syndrome; CoQ10=Coenzyme Q10; CPAP=Continuous Positive Airway Pressure; DB-RCT=Double Blind Randomized Controlled Trial; DoD=Department of Defense; GI=Gastrointestinal; GW=Gulf War; GWI=Gulf War Illness; IBS=Irritable Bowel Syndrome; MBB=Mind-Body Bridging; MBSR=Mindfulness-based Stress Reduction; NR=Not Reported; Pts=Participants; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of Bias; SD=Standard Deviation; SED=Sleep Education; TAU=Treatment as Usual; Tx=Treatment; VA=Veterans Affairs

### Medications

We found 4 trials of medications (doxycycline,^1^ mifepristone,^2^ naltrexone,^3^ and rifaximin^4^; Table 3; Study characteristics in Table 2; Detailed results in Appendix D, Tables 9–11). A large (N=491), adequately-powered, 12-month study of doxycycline (200 mg/day) provided moderate-strength evidence of no benefit and greater risk of adverse effects, such as nausea and photosensitivity, with treatment compared with placebo.^1^ Study retention in the doxycycline group was similar to that of the placebo group (80% versus 82.5%), and adherence was rated “good or excellent” in 77.5% versus 74.5% of participants at 6 months, and 65.6% versus 66.6% at 12 months.^1^ A 2-week study of rifaximin^4^ (550 mg twice per day) in patients with IBS found no effect on IBS symptoms or quality of life; we rated the evidence insufficient because there was only 1 small study that analyzed only the participants who completed treatment (92.6% in rifaximin vs 82.6% placebo). Studies of mifepristone^2^ (200 mg/day for 3 weeks) and naltrexone^3^ (4.5 mg/day for 3 months) were rated as insufficient due to methodologic limitations such as small sample size^2^ and concerns with allocation concealment^3^ (more details on quality are presented in Appendix C, Table 8; Information on harms is in Table 12). Attrition was low in both studies, with 97% of randomized participants completing treatment in the mifepristone study^2^ and 92.5% completion in the naltrexone study.^3^

Table 3 Summary of the effectiveness and strength of evidence from placebo-controlled trials of medications for treating symptoms of Gulf War Illness

| Doxycycline^1^ | Mifepristone^2^ | Naltrexone^3^ | Rifaximin^4^
Study characteristics
Sample size | N=491 | N=36 | N=40 | N=50
ROB | Low | Some concerns | High | Some concerns
Summary of effectiveness (strength of evidence) of treatment vs placebo, by symptom domain
Physical health overall | No difference (Moderate) | No difference (Insufficient) | No difference (Insufficient) | ---
Pain | No difference (Moderate) | --- | --- | ---
Cognitive | No difference (Moderate) | Mixed findings (Insufficient) | No difference (Insufficient) | ---
Fatigue | No difference (Moderate) | No difference (Insufficient) | --- | ---
Mental health overall | No difference (Moderate) | No difference (Insufficient) | --- | ---
Depression | --- | No difference (Insufficient) | --- | ---
Global outcomes function, QoL | --- | --- | --- | No difference (Insufficient)
PTSD symptoms | --- | No difference (Insufficient) | --- | ---
Sleep | --- | --- | --- | ---
GI symptoms | --- | --- | --- | No difference (Insufficient)
Adverse events | Favors placebo (Moderate) | Unclear (Insufficient) | Unclear (Insufficient) | No difference (Insufficient)

Abbreviations: GI=Gastrointestinal; N=Number of participants; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of bias; SOE=Strength of Evidence

### Nutritional supplements

Two high-ROB trials of nutritional supplements (carnosine^5^ and CoQ10^6^) found some evidence of benefit on various GWI symptoms (Table 4; Study characteristics in Table 2; Detailed results in Appendix D). The SOE for these findings is insufficient due to methodologic limitations including selective outcome reporting in the CoQ10 trial^6^ and potential deviation from the intended interventions in the carnosine trial.^5^

The trial of carnosine (500 mg/day increasing to 1500 mg/day over 12 weeks) in 34 patients with IBS found positive effects on cognitive function and gastrointestinal (GI) symptoms, but no difference on pain and fatigue (see Appendix D).^5^ At 12 weeks, the proportion of participants with no IBS symptoms increased from 30% to 43% compared with baseline in the carnosine group, but remained 33% in the placebo group (P = 0.019). Symptoms of stool frequency and watery consistency reduced with carnosine but did not change with placebo. The carnosine group had significantly lower WAIS-R scores at week 12 compared with placebo (P = 0.013). Because the WAIS-R scores were lower in the carnosine group at baseline, the effect of carnosine on cognitive symptoms is inconclusive. The authors report that study compliance was excellent based on diaries and pill counts, though this was not biologically verified. With regard to attrition, 9 of the 34 participants dropped out prior to the study ending (5 from the carnosine group and 4 from placebo). Two were terminated due to health issues determined to be unrelated to treatment, 4 were lost to follow-up, and 3 dropped out after 6 weeks due to “frustration about lack of improvement”.^5^

A 4-month trial of CoQ10 (N = 46; n = 11 on 100 mg/day, n = 12 on 300 mg/day for 4 months) found improvement on overall physical health (differences in Summary Performance Score of 42% for 100 mg/day versus placebo [P = 0.025] and 15% for 300 mg/day versus placebo [P = 0.44]) but the threshold for improved versus not improved was not clearly defined.^6^ No difference in cognitive symptoms was observed. Adherence was not reported for this trial. Attrition was minimal; 1 dropout in the treatment arm due to a stroke, and 3 in the placebo arm due to logistical reasons (2) and lost to follow-up (1).

Table 4 Summary of the effectiveness and strength of evidence from placebo-controlled trials of nutritional supplements for treating Gulf War Illness, by symptom domain

| Carnosine^5^ | CoQ10^6^
Study characteristics
Sample size | N=34 | N=46
ROB | High ROB | High ROB
Summary of effectiveness (strength of evidence) of treatment vs placebo
Physical health overall | --- | Favors CoQ10 (Insufficient)
Pain | No difference (Insufficient) | ---
Cognitive | Favors carnosine (Insufficient) | No difference (Insufficient)
Fatigue | No difference (Insufficient) | ---
Mental health overall | --- | ---
Depression | --- | ---
Global outcomes (function, QoL) | --- | ---
PTSD symptoms | --- | ---
Sleep | --- | ---
GI symptoms | Favors carnosine (Insufficient) | ---
Adverse events | No difference (Insufficient) | No difference (Insufficient)

Abbreviations: GI=Gastrointestinal; N=Number of Participants; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of Bias; SOE=Strength of Evidence

### Psychological, exercise, and multi-component interventions

This category of treatments for GWI includes 2 mindfulness-based interventions,^9,10^ a detox regimen,^8^ and a multi-arm trial of CBT with and without exercise^7^ (see Table 2 for study characteristics; Table 5 for a summary of the evidence; and Appendix D, Tables 9–11 for detailed results). The 2 mindfulness approaches had somewhat inconsistent results. The first was a trial of MBSR (N = 55) – a program focused on increasing present moment awareness and acceptance of thoughts, emotions and sensations – which was delivered in 8 weekly, 2.5-hour sessions, plus 1 7-hour session.^9^ It found that MBSR improves pain, cognitive functioning, fatigue, depression and PTSD symptoms among those with GWI compared to treatment as usual (TAU; low SOE). Improvements on all outcomes were retained at the 6-month follow up, with the exception of PTSD symptoms (detailed study information located in Table 2 and Appendix D).^9^ Seventy-three percent of the intervention arm were classified as completers, defined as having attended 4 out of 8 classes. Attrition for TAU was not reported. Intention-to-treat (ITT) and completer analyses were performed and had similar results. With regard to follow-up data, 22 (85%) of those in the MBSR arm contributed 6-month follow-up data compared to 23 (79%) of those in the TAU arm.^9^

Another trial of a mindfulness-based approach, MBB (N = 60) taught participants to stay in the present moment when trying to fall asleep, as well as skills to manage stress and emotional reactivity to stressful thoughts over 3 sessions.^10^ The comparator group received 3 Sleep Hygiene Educational (SED) sessions focused on improving routine and habits around sleep. MBB was found to improve fatigue, depression, PTSD and sleep, but did not improve overall physical or mental health, pain or cognitive functioning compared to SED. Of the initial 60 participants who were randomized to MBB (33) versus SED (27), 57 participants completed the intervention, indicated by their attending at least 2 sessions (31 [93.9%] versus 26 [96.3%]). A total of 55 completed the post assessment (29 [87.9%] versus 26 [93.9%]), and 49 completed the follow-up assessment (24 [72.7%] versus 25 [92.6%]). Reasons for attrition were not reported.^10^

In the trial of CBT and exercise,^7^ 1,092 Veterans were randomly assigned to 1 of 4 groups: (1) TAU (n=271), which consisted of any and all care received from inside and outside the VA; (2) CBT and TAU (n=286) which added 12 weekly, 60–90 minute CBT group sessions that taught behavioral and cognitive skills to enhance coping and problem-solving; (3) TAU and exercise (n= 269) which added 12 weekly, 60-minute low-intensity aerobic exercise sessions; and (4) TAU with CBT and exercise (n= 266). Global physical health improvement was defined as a 7-point or greater increase on the Physical Component Scale (PCS) of the Veteran Short Form 36-Item Health Survey (VF-36). Among those who received CBT, exercise, or a combination of the 2, there was evidence of modest benefit (marginal effect) for up to 1 year after the intervention completion on several GWI symptom domains, including measures of physical health fatigue, cognitive functioning, distress, and mental health functioning (moderate SOE). The intervention adherence rates, defined as attending two-thirds of sessions, ranged from a low of 36% among those in the CBT only arm to a high of 47% for exercise only. Table 2 contains detailed study information, and results are in Appendix D.

Finally, the detox regimen study used a pragmatic, parallel design, to randomize 32 participants to either a daily regimen of exercise, sauna-induced sweating, crystalline nicotinic acid, and other supplements for 4–6 weeks (n=22) or waitlist control (n=10; Detailed study information located in Table 2, and results in Appendix D).^8^ The intervention was found to improve pain, fatigue, and overall mental health, yet there was no difference on global QoL compared to placebo; methodological limitations such as limited sample size and selective outcome reporting inhibited our ability to have confidence in the conclusions. As such, outcomes from this detox regimen were all rated insufficient SOE. All 32 participants completed the intervention and 21 completed the 3-month follow up.^8^

The ROB for all psychosocial intervention studies was classified as “some concerns” primarily because of utilizing self-reported outcomes without blinding of participants as to which intervention group they were in. There are methodical ways to do this including using sham treatment as a control in some cases. We outline the pros and cons of such blinding procedures in the discussion. Another limitation of this body of literature is that the potential harms of these interventions were not well characterized – as was the case in the MBSR trial – or it was unclear whether the AEs were related to the intervention or not – as was the case in the CBT/Exercise trial. The detox intervention may place individuals at a higher risk of AEs; yet there may be promising effects of the mindfulness-based approaches and the combination of CBT and exercise (See Appendix C, Table 8 for ROB ratings, and Appendix D, Table 12 for AE details).

Table 5 Summary of the effectiveness and strength of evidence from trials of psychological, exercise, or multi-component interventions for treating GWI, by symptom domain

| CBT/Exercise/combined CBT + Exercise^7^ | Detox regimen^8^ | Mindfulness-based stress reduction^9^ | Sleep focused mind-body bridging^10^
Study characteristics
Comparator | TAU | Waitlist | TAU | Sleep education
Sample size | N=1092 | N=32 | N=55 | N=60
ROB | Some concerns | Some concerns | Some concerns | Some concerns
Summary of effectiveness (strength of evidence) of treatment vs comparator
Physical health overall | Favors CBT (Moderate) | Mixed findings (Insufficient) | --- | No difference (Insufficient)
Pain | Favors CBT; Favors combined CBT + exercise (Moderate) | Favors detox (Insufficient) | Favors MBSR (Low) | No difference (Insufficient)
Cognitive | Favors CBT; Favors exercise; Favors combined CBT + exercise (Moderate) | --- | Favors MBSR (Low) | No difference (Insufficient)
Fatigue | Favors combined CBT + exercise (Moderate) | Favors detox (Insufficient) | Favors MBSR (Low) | Favors MBB (Low)
Mental health overall | Favors exercise; Favors combined CBT + exercise; Mixed findings CBT (Moderate) | Favors detox (Insufficient) | --- | No difference (Insufficient)
Depression | --- | --- | Favors MBSR (Low) | Favors MBB (Low)
Global outcomes (function, QoL) | --- | No difference (Insufficient) | --- | No difference (Insufficient)
PTSD symptoms | --- | --- | Favors MBSR (Low) | Favors MBB (Low)
Sleep | --- | --- | --- | Favors MBB (Low)
GI symptoms | --- | --- | --- | ---
Adverse events | Unclear (Insufficient) | Favors usual care (Insufficient) | --- | ---

Abbreviations: CBT=Cognitive Behavioral Therapy; GI=Gastrointestinal; MBB=Mind-body Bridging; MBSR=Mindfulness-based Stress Reduction; N=Number of Participants; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of Bias; SOE=Strength of Evidence; TAU=Treatment as Usual

### Other interventions (acupuncture, CPAP)

Two other interventions were identified (Table 6; Detailed study information in Table 2; and results in Appendix D). A trial of acupuncture^11^ (N = 104) with some concerns for ROB found that overall physical health (P = 0.03; SE 3.76 [95% CI: 1.03 to 15.76]) and pain (P = 0.04; SE 1.71 [95% CI: −6.95 to −0.2]) significantly improved in the treatment arm versus wait list. Treatment consisted of individualized acupuncture protocols twice a week for 6 months compared to 2 months on a waitlist followed by once-weekly individualized acupuncture protocols. After 2 months, 90% of participants randomized to 2 sessions per week remained in the study, and 84.6% of those randomized to waitlist were available to receive treatment. Eighty-two percent (85 out of 104 randomized) completed the 6-month follow up assessment. Pain on needling was reported as an AE, but despite that, 96% of participants reported that they would recommend acupuncture.^11^ The SOE was insufficient owing to lack of blinding with self-reported outcomes.

A low-ROB trial of CPAP among Veterans with GWI and sleep disordered breathing reported favorable results on multiple outcomes (low SOE).^12^ The trial compared the use of CPAP at individualized pressure levels with sham CPAP (pressure below 1 cmH_2_O) for 5 hours per night over 3 weeks. Although CPAP is an evidence-based treatment for sleep apnea, CPAP was also associated with improvement among a broader range of GWI symptoms in this study than just sleep outcomes. Specifically, significant improvements were found for pain (effect size: 2.14; P = 0.0008), fatigue (effect size: 2.55; P = 0.0002), cognitive function (effect size: 1.67; P = 0.004), sleep quality (effect size: 2.67; P = 0.0003), physical health (effect size: 2.79; P = 0.0003), and mental health (effect size: 1.29; P = 0.03). Compliance with assigned treatment was comparable between the active and sham groups (265.1 ± 90.2 minutes/night versus 266.6 ± 100.8 minutes/night, respectively; P = 0.98). Participants were 100% compliant with mailing back their questionnaires. One participant assigned to active treatment was enrolled in a PTSD treatment program and excluded. While methodologically the CPAP trial had low ROB, because the trial was small (N=18) more trials are needed to characterize the benefits with confidence.

Table 6 Summary of the effectiveness and strength of evidence from trials of acupuncture and CPAP in Veterans with Gulf War Illness

| Acupuncture^11^ | CPAP^12^
Study characteristics
Comparator | Waitlist | Sham CPAP
Sample size | N=104 | N=18
ROB | Some concerns | Low ROB
Summary of effectiveness (strength of evidence) of treatment vs comparator
Physical health overall | Favors acupuncture (Insufficient) | Favors CPAP (Low)
Pain | Favors acupuncture (Insufficient) | Favors CPAP (Low)
Cognitive | --- | Favors CPAP (Low)
Fatigue | --- | Favors CPAP (Low)
Mental health overall | --- | Favors CPAP (Low)
Depression | --- | ---
Global outcomes (function, QoL) | --- | ---
PTSD symptoms | --- | ---
Sleep | --- | Favors CPAP (Low)
GI symptoms | --- | ---
Adverse events | Unclear (Insufficient) | ---

Abbreviations: CBT=Cognitive Behavioral Therapy; GI=Gastrointestinal; MBB=Mind-body Bridging; MBSR=Mindfulness-based Stress Reduction; N=Number of Participants; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of Bias; SOE=Strength of Evidence

## KEY QUESTION 2 Do the effectiveness or harms of the interventions/strategies differ among subgroups of Veterans with GWI, such as female Veterans or cases defined by specific criteria, in comparison with Veterans with GWI overall?

We found no studies that compared the effects of an intervention in a subpopulation with a broader sample of GWI patients. Four studies included in KQ1 limited their inclusion criteria to specific symptoms or subpopulations (IBS in a study of rifaximin,^4^ sleep-disordered breathing in a study of CPAP,^12^ sleep disturbance in a study of mind-body bridging,^10^ and patients positive for mycoplasma DNA in a study of doxycycline^1^). Although the findings of these studies may be most applicable to the targeted subpopulations, we are not able to draw conclusions about whether the treatments affect symptoms differently in these subpopulations compared with GWI patients overall.

## KEY QUESTION 3 What interventions for GWI have been examined in noncomparative studies and ongoing/unpublished trials or cohort studies?

### Summary of Findings

We found 31 ongoing or unpublished trials and 2 published noncomparative intervention studies. Although 2 of the clinical trials were terminated before completion, we have included them in the characterization of current research in this area so that future researchers are aware of what interventions have been attempted. A brief list of the interventions, comparators, projected sample sizes, and targeted symptom or subpopulations are shown in Table 7. Detailed information about each study is provided in Appendix D, Table 13.

We identified 33 ongoing, single-arm pilot, or unpublished studies of treatments for GWI symptoms in the following areas: behavioral and psychological interventions (4), various forms of central nervous system stimulation devices (5), complimentary and integrated health interventions including movement therapies (4), dietary interventions (2), exercise (1), medications (7), nutritional supplements (7), stochastic noise electrical stimulation (1), nasal irrigation (1), and light-emitting diode (LED) therapy (1). These represent a much broader range of interventions than completed trials included in our question about effectiveness (KQ1) with only a few treatments that have been tested in earlier trials: 2 of cognitive behavioral approaches, 1 of MBSR, and 1 with an acupuncture component. Aside from 2 ongoing studies examining forms of transcranial direct current stimulation (tDCS), and 3 examining repetitive transcranial magnetic stimulation (rTMS), no 2 ongoing studies address the same intervention, and the interventions examined by the remaining 22 studies vary widely (See Appendix D, Table 13).

Because many of these studies are ongoing, we were not able to rate the ROB for the individual studies or draw conclusions. Four RCTs have made results publicly available, although 3 did not report between-group statistical analyses. Preliminary results (N=17) from 1 crossover RCT of a low-glutamate diet found significant improvement in PTSD and anxiety (see Appendix D, Table 15).^25^

Two additional single-arm pilot studies also showed a pre-post treatment effect, but these results would need to be replicated in a larger sample and may suggest future areas of research (see Appendix D, Table 16).

Table 7 Interventions for GWI in ongoing/unpublished clinical trials and single-arm studies

Intervention category | Treatment | Comparator | Sample size^*^ | Targeted symptom or subpopulation | Status
Behavioral | CBT^26^ | Waitlist | 80 | Insomnia | Ongoing
Behavioral | Cognitive rehabilitation^27^ | Health education | 268 | --- | Completed, no results posted
Behavioral | Mindfulness-Based Stress Reduction^28^ | Adapted CDSMP | 308 | --- | Ongoing
Behavioral, multicomponent | Specialized Care Program^29^ | No comparator | 109 | --- | Published
CNS stimulation | (HD) tDCS^30^ | Sham HD tDCS | 120 | --- | Ongoing
CNS stimulation | rTMS^23^ | Sham rTMS | --- | Chronic musculoskeletal pain | Terminated before completion
CNS stimulation | rTMS^31^ | Sham rTMS | 90 | Migraines, and muscle/ joint pain | Ongoing
CNS stimulation | rTMS^32^ | Sham rTMS | 80 | Migraines, muscle/ joint pain, and depression | Ongoing
CNS stimulation | rTMS^33^ | Sham rTMS | 150 | Headaches and pain | Ongoing
CNS stimulation | tDCS^34^ | Sham tDCS | 120 | --- | Ongoing
CNS stimulation | VNS^35^ | Placebo | 40 | Widespread pain and migraines | Ongoing
Complementary and integrative health | Acupressure^36^ | Reiki | 7 | Pain and fatigue | Completed, no results posted
Complementary and integrative health | Meditation + acupuncture^37^ | GW Health education | 172 | --- | Ongoing
Complementary and integrative health | Tai Chi^38^ | Wellness intervention (video and mindfulness) | 120 | Joint pain/stiffness | Ongoing
Complementary and integrative health | Yoga^39^ | CBT | 75 | Chronic pain | Completed, results posted
Diet | Low-FODMAP diet^40^ | High-FODMAP diet | 68 | IBS | Completed, no results posted
Diet | Low-glutamate diet^41,42^ | Waitlist | 40 | --- | Ongoing
Exercise | Exercise training^43^ | Waitlist | 77 | Chronic musculoskeletal pain | Completed, no results posted
Medication | D-cycloserine^44^ | Placebo | 56 | Cognitive symptoms | Ongoing
Medication | Duloxetine vs pregabalin^24^ | Placebo | --- | Pain | Terminated before completion
Medication | Etanercept+ mifepristone^45^ | No comparator | 20 | Safety | Ongoing
Medication | Intranasal insulin^46^ | Placebo | 114 | Cognitive symptoms | Ongoing
Medication | Prednisone^47^ | Placebo | 100 | --- | Ongoing
Medication | Pregnenolone^48^ | Placebo | 170 | --- | Completed, no results posted
Medication | Rituximab^49^ | Placebo | NR | --- | Ongoing
Medication + nutritional supplement | Nutrient formula + methylphenidate^50^ | No comparator | 15 | --- | Published
Nutritional supplement | Botanical Microglia Modulators^51^ | Placebo | 64 | --- | Ongoing
Nutritional supplement | Concord grape juice^52^ | Placebo | 36 | --- | Completed, no results posted
Nutritional supplement | Mitochondrial cocktail^53^ | Placebo | NR | --- | Ongoing
Nutritional supplement | Resveratrol^54^ | Placebo | 68 | --- | Ongoing
Nutritional supplement | Ubiquinol (CoQ10)^55^ | Placebo | 200 | --- | Ongoing
Nutritional supplement | Visbiome vs VSL#3^56^ | Placebo | 60 | IBS | Ongoing
Other | Electrical stimulation (stochastic noise)^57^ | Sham electrical stimulation | 60 | Vestibular function; postural sway | Completed; unpublished
Other | LED therapy^58^ | Sham LED | 160 | Neuropsychological symptoms | Ongoing
Other | Nasal irrigation (Xylitol)^59,60^ | Saline NI; Usual care | 40 | Chronic rhinosinusitis | Completed, results posted

* projected sample size, actual size may differ

Abbreviations: CDSMP=Chronic Disease Self-Management Program; CN =Central Nervous System; CoQ10=Coenzyme Q_10_; FODMAP=Fermentable Oligo-, Di-, Mono-saccharides and Polyols; GW=Gulf War; HD tDCS=High Definition Transcranial Direct Current Stimulation; LED=Light-emitting Diodes; NI=Nasal Irrigation; NR=Not Reported; rTMS=Repetitive Transcranial Magnetic Stimulation; tDCS=Transcranial Direct Current Stimulation; VNS=Vagus Nerve Stimulation; VSL=Very Safe Lactobacilli

### Ongoing and Unpublished Studies – Detailed Findings

#### Behavioral interventions

Two randomized controlled trials (1 in progress^26^ and 1 unpublished but completed^27^) are testing CBT for GWI. The ongoing study^26^ is testing telephone-delivered, insomnia-focused CBT for Veterans with GWI and insomnia compared to usual care, and the other trial tested problem-solving therapy for cognitive rehabilitation compared to health education in GWI Veterans.^27^ A third, ongoing behavioral study is comparing MBSR to a Chronic Disease Self-Management Program (CDSMP) in Veterans with CMI.^28^ A subset of the study population will be Gulf War Veterans. No results are available yet for these studies (Appendix D, Table 13).

#### Brain stimulation therapy

Six RCTs are testing brain stimulation therapies (Appendix D, Table 13).^30–35^ Three studies are examining rTMS versus sham rTMS, 2 are investigating tDCS versus sham tDCS,^30,34^ and 1 is studying vagus nerve stimulation (VNS) versus sham VNS.^35^ Three of the 6 trials required participants have migraines in addition to GWI in their inclusion criteria.^31,32,35^ One additional study of rTMS was terminated due to low enrollment.^23^ Results have not been reported for any of these RCTs.

#### Complementary and integrative health (CIH)

Four trials examined CIH interventions (Appendix D, Table 13).^36–39^ One nRCT of acupressure versus reiki for GWI-related fatigue and pain^36^ was completed in 2017, but has not posted results; an ongoing RCT is examining Tai Chi compared to a wellness intervention for pain and other GWI symptoms^38^; and 1 ongoing RCT is studying meditation (iRest Yoga Nidra) with auricular acupuncture compared to a GW health education control for improving sleep quality in Veterans with GWI.^37^

The fourth study is an RCT completed in early 2018 comparing yoga to CBT for pain in Veterans with GWI.^39,61^ This trial reported results for change in within-group mean pain scores measured by the Brief Pain Inventory-Short Form (BPI-SF) from baseline to end of treatment and found that the yoga group improved significantly (P < 0.001), but the CBT group did not (P > 0.05).^39,62^ At 6-month follow-up the yoga group still had significantly improved pain scores compared to baseline (P = 0.02), while CBT mean change scores were not reported.^39,62^ No between-groups analysis was reported (Results in Appendix D, Table 15).

#### Diet

Two RCTs are examining the effects of dietary interventions on Veterans with GWI (Appendix D, Table 13).^40,41^ One study, that was estimated to have been completed in 2018, compared a low-FODMAP (Fermentable Oligo-, Di-, Mono-saccharides And Polyols) diet to a typical healthy (high-FODMAP) diet for IBS in GW Veterans, but results are not yet reported.^40^

The other dietary RCT is a crossover study examining a low-glutamate diet and subsequent monosodium glutamate (MSG) challenge.^41^ This trial is ongoing but has reported some preliminary results for 17 participants.^25,41^ The outcomes analyzed were PTSD symptoms measured by the PTSD Checklist – Civilian version (PCL-C) and anxiety measured by the Generalized Anxiety Disorder 7-item scale (GAD-7). Median scores were reduced significantly over 1-month intervention (PCL-C score P = 0.04; GAD-7 score P = 0.01; Appendix D, Table 15).

#### Electrical stimulation

In 1 trial, the investigators developed a novel portable electrical stimulation device that provides random, imperceptible stochastic noise via ear clips, intended to improve vestibular function (Appendix D, Table 13).^57,63^ Worn constantly during the 12-week trial, it improved ocular torsion (OT) and sway compared to a sham stimulator (Appendix D, Table 15).^57,63^

#### Exercise

One RCT tested 16 weeks of resistance exercise training compared to a waitlist control for physical symptoms including chronic pain in Veterans with GWI.^43^ Completed at the end of 2018, results of the trial are not yet available.

#### Light-Emitting Diodes therapy

One crossover RCT is comparing a course of LED treatment to sham LED treatment for cognitive symptoms in GWI Veterans (Appendix D, Table 13).^58^ The study is ongoing.

#### Medications

Seven RCTs examined pharmacological interventions for Veterans with GWI symptoms (Appendix D, Table 13).^24,44–49^ One RCT studying adjunctive pregnenolone for fatigue, musculoskeletal pain, and cognitive decline in GW veterans^48^ was completed in 2018, but has not posted results; 1 small Phase I trial of the combination of etanercept and mifepristone is testing 2 doses of mifepristone (300mg and 600mg) and the primary outcome is safety^45^; 1 RCT, estimated to have been completed in 2017, examined whether intranasal insulin improves cognitive function and other CMI symptoms in GW veterans with CMI^46^; an ongoing RCT of treatment with delayed-release prednisone seeks to determine if it improves the health-related QoL of Veterans with GWI^47^; 1 ongoing RCT is investigating the efficacy of d-cycloserine treatment for GWI^44^; and 1 ongoing RCT is evaluating GWI symptom improvement with the use of b-cell depletion therapy with rituximab.^49^ One RCT was testing the treatments of duloxetine and pregabalin for Veterans with GWI, but the study was terminated by the funder in 2019, and no reason was given.^24^

#### Nasal irrigation

One RCT examined the effectiveness of nasal irrigation with either xylitol or saline versus placebo for chronic rhinosinusitis (CRS) in Veterans with GWI (Appendix D, Table 13).^60^ Changes from baseline in fatigue (measured by the Multidimensional Fatigue Inventory [MFI]) and respiratory scores (measured by the 20-item Sinonasal Outcome Test [SNOT-20]) were reported for the 40 participants at weeks 8 and 26 of treatment, but no statistical analyses were presented (Appendix D, Table 15).^59^

#### Nutritional supplements

Six recent trials examined the effects of nutritional supplements on veterans experiencing GWI symptoms (Appendix D, Table 13).^51–56^ One RCT tested the consumption of Concord grape juice for treating cognitive deficits and chronic fatigue in Veterans with GWI^52^ was completed in 2019, but has not posted results; 1 controlled trial estimated to have been completed in 2019 examined the benefit of a mitochondrial supplement with an individualized correction or citric acid cycle (CAC) intermediates and amino acid (AA) abnormalities as part of a mitochondrial/oxidative stress treatment approach in GWI^53^; 1 RCT estimated to have been completed in 2018 examined Visbiome and its effects on IBS and non-intestinal symptoms such as fatigue, joint pain, insomnia, general stiffness and headache, associated with IBS^56^; 1 ongoing RCT is using resveratrol as a treatment to improve memory issues, difficulties with thinking and mood problems in Veterans with GWI^54^; 1 ongoing RCT is determining the use of ubiquinol and its effectiveness to improve the physical function in Veterans with GWI^55^; and 1 ongoing crossover RCT is examining various botanical compounds and their effectiveness in suppressing symptoms of GWI.^51^

### Single-arm Studies with Published Results

Two published single-arm pre-post studies of interventions for GWI were identified in our search (Appendix D, Tables 14 and 16).^29,50^ First, in a specialized care program (SCP) of 109 Veterans, improvements were seen on global physical health outcomes that were maintained at 3-month follow-up.^29^ The program was a 3-week intensive outpatient group program that included the development of an individualized symptom-management plan that combined regular primary medical care, exercise, self-care, and other active coping strategies.^29^

The other single-arm study was of 15 Veterans with GWI treated with a nutrient formula and methylphenidate for 12 weeks.^50^ Participants improved on measures of fatigue, sleep, cognitive symptoms, and an assessment of GWI symptoms overall, but the small size and lack of comparison group precludes drawing any conclusions from results.