# Methods

## Topic Development

The key research questions for the review were as follows:

1. Evidence on effectiveness/harms: What are the benefits and harms of pharmacological and non-pharmacological interventions and management strategies for Veterans with GWI?
2. Evidence about subgroups: Do the effects of the interventions differ among subgroups Veterans with GWI in direct comparison with a larger sample of GWI patients?
3. Emerging research: What interventions for GWI have been examined in:
  a) noncomparative studies only?
  b) ongoing/unpublished trials or cohort studies?

Our approach was guided by the conceptual framework we developed in consultation with our operational partners (Figure 1).

Figure 1 Conceptual framework

Note. Numbers in grey bubbles refer to Key Questions

Abbreviations: GWI=Gulf War Illness; QoL=quality of life

## Search Strategy

We conducted a primary review of the literature by systematically searching, reviewing, and analyzing the scientific evidence as it pertains to the research questions. To identify relevant articles, we searched Ovid MEDLINE, Ovid PsycINFO, Ovid EBM Reviews (Cochrane Database of Systematic Reviews and Cochrane Central Register of Controlled Trials), CINAHL, and Allied and Complementary Medicine Database (AMED) through September 17, 2019. Search strategies were developed in consultation with a research librarian, and peer reviewed by a second research librarian using the instrument for Peer Review of Search Strategies (PRESS).^19^ The search strategy included terms to identify Veterans from the Gulf War era (eg, Desert Shield, Desert Storm, Kuwait War, Operation GRANBY) combined with past and present terms to identify Gulf War Illness (eg, chronic multisymptom illness, chronic fatigue, Gulf War Syndrome). We limited our search to English-language publications but did not limit by publication status or study design. To identify in-progress or unpublished studies, we searched ClinicalTrials.gov and the World Health Organization (WHO) International Clinical Trials Registry Platform (ICTRP; the full search strategies are in Appendix A). We reviewed the bibliographies of relevant articles and contacted experts to identify additional studies.

## Study Selection

Criteria for population, interventions, comparators, outcomes, timing, and setting (PICOTS; Table 1) were developed in collaboration with our operational partners and Technical Expert Panel. Two ESP-reviewers independently assessed studies for inclusion based on pre-specified criteria. All discordant results were resolved through consensus or consultation with a third ESP-reviewer. Articles meeting eligibility criteria were included for data abstraction.

For evidence on effectiveness, harms, and subgroups, eligible study designs included RCTs, nRCTs, and cohort studies in Veterans with GWI that directly compared interventions against each other, placebo, or usual care. To be included, both the intervention and comparator groups had to consist of a population of Veterans with GWI. If there was a mix of participants with and without GWI, we only included the study if the GWI population was analyzed separately. For Key Question (KQ) 3 on emerging research, we also included noncomparative intervention studies such as pilot/feasibility studies or case series.

Table 1 PICOTS by Key Question

Key Question: | KQ1. evidence on effectiveness and harms:; What are the (a) benefits and (b) harms of interventions and management strategies for Veterans with GWI? | KQ2. evidence about subgroups:; Do the effects of the interventions differ among subgroups in direct comparison with a larger sample of GWI patients? | KQ3. emerging research:; What interventions for GWI have been examined in:; a) noncomparative studies only?; b) ongoing/unpublished trials or cohort studies?
Population | Veterans with GWI who were deployed to the Persian Gulf region between Aug 2, 1990 - Nov 1991. Include international Veteran populations (countries that deployed troops there^*^; but limit to English-language publications). Include studies of civilian contractors present during the conflict, if available. Include studies where deployment status is unclear because diagnosis was made according to CDC/Fukuda 1998 criteria.^14^ | Subpopulations may include but are not limited to the following:; - Gender; - Case definition; - Severity of symptoms; - Branch of military; Studies that include only members of a specific subgroup and do not compare findings to Veterans with GWI overall would address KQ1 only. | Veterans with GWI who were deployed to the Persian Gulf region between Aug 2, 1990 - Nov 1991. Include international veteran populations (countries that deployed troops there^*^; but limit to English-language publications). Include studies of civilian contractors present during the conflict, if available. Include studies where deployment status is unclear because diagnosis was made according to CDC/Fukuda 1998 criteria.^14^
Intervention | Pharmacological and nonpharmacological interventions or management strategies for Gulf War Illness
Comparators | Another active intervention, placebo, or usual care. | | Another active intervention, placebo, usual care, or no comparator (eg, single-arm pilot study).
Outcomes | Outcomes of interest are the 3 symptom domains that occur in both the CDC and Kansas case definitions: cognitive function, fatigue, and pain. Other outcomes of interest:; - Additional symptom domains used in the Kansas case definition (sleep, mood, musculoskeletal, gastrointestinal, respiratory, dermatological); - Global outcomes (eg, QoL and measures of function); - PTSD; - Adverse effects of treatment
Timing | No limits
Settings | No limits
Study Design | RCT, nRCT, cohort, SRs/MAs | | Unpublished or in-progress comparative studies (RCT, nRCT, cohort, SRs/MAs) and case series/single-arm pilot studies of interventions not examined in comparative studies. Exclude case reports.

* We recognize other countries may use different case definitions

Abbreviations: CDC=Centers for Disease Control and Prevention; GWI=Gulf War Illness; KQ=Key Question; MA=Meta-Analysis; nRCT=non-Randomized Controlled Trial; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; RCT=Randomized Controlled Trial; SR=Systematic Review

## Data Abstraction

Data from studies meeting inclusion criteria were abstracted by 1 ESP reviewer and confirmed by at least 1 additional ESP reviewer. From each study, we abstracted the following where available: study design, sample size, setting, population characteristics, participant inclusion and exclusion criteria, the study and comparator interventions including dosage, timing, and duration of treatment, duration of follow-up, adjunctive interventions, adverse effects, and findings according to GWI outcome domains (cognitive function, fatigue, pain, sleep, mood, QoL, musculoskeletal, gastrointestinal, respiratory, and dermatological).

## Quality Assessment

Two ESP-reviewers independently assessed the risk of bias (ROB) of each study. To assess the ROB of RCTs we used the Revised Cochrane Risk-of-Bias criteria, RoB 2.0.^20^ Disagreements were resolved by consensus or a third ESP-reviewer. The ROB assessment criteria and our ratings for each study are shown in Appendix C.

## Data Synthesis

We qualitatively synthesized the evidence and compiled evidence tables of study characteristics and findings for each key question, grouping outcomes and interventions across studies when indicated. We were not able to conduct meta-analyses of interventions because there were not enough studies with similar characteristics of similar interventions to allow meaningful quantitative analysis.

## Rating the Body of Evidence

We assessed the overall strength of evidence (SOE) for each outcome using a method developed for the Agency for Healthcare Research and Quality’s (AHRQ) Evidence-based Practice Centers (EPCs).^21^ The AHRQ EPC method considers study limitations, directness, consistency, precision, and reporting bias to classify the SOE for individual outcomes independently for RCTs and observational studies, with supplemental domains of dose-response association, plausible confounding that would decrease the observed effect, and strength of association, as well as separate guidance for applicability.^22^ Ratings were categorized as follows:

- High=Very confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has few or no deficiencies, the findings are stable, and another study would not change the conclusions.
- Moderate=Moderately confident that the estimate of effect lies close to the true effect for this outcome. The body of evidence has some deficiencies and the findings are likely to be stable, but some doubt remains.
- Low=Limited confidence that the estimate of effect lies close to the true effect for this outcome. The body of evidence has major or numerous deficiencies (or both). Additional evidence is needed before concluding either that the findings are stable or that the estimate of effect is close to the true effect.
- Insufficient=Unable to estimate an effect, typically because there were too few studies, with very small sample sizes, and often with methodologic flaws.
- No evidence=No studies.