# Introduction

After the 1990–1991 conflict in the Persian Gulf, many Gulf War Veterans began reporting numerous unexplained symptoms including, but not limited to, systemic pain, fatigue, flu-like symptoms and difficulty with memory/concentration. These symptom clusters were initially classified as Persian Gulf War Syndrome, then more generally under the broader umbrella of Chronic Multisymptom Illness (CMI), and most recently as Gulf War Illness (GWI).^13^ The 2 most widely recognized case definitions of GWI —recommended for use by the Department of Defense (DoD) and Department of Veterans Affairs (VA)—are the Centers for Disease Control and Prevention (CDC)^14^ and Kansas^15^ definitions. The CDC definition defines a case as having at least 1 symptom from 2 of 3 categories (fatigue, mood and cognition, and musculoskeletal) for 6 months or longer.^14^ The Kansas approach defines a case as having 1 moderately severe, or 2 or more chronic, symptoms in at least 3 of 6 domains (including fatigue or sleep, pain, neurologic or cognitive or mood, gastrointestinal, respiratory, and skin).^15^ While both case definitions require the onset of symptoms to be within 6 months of deployment, this onset criteria is not consistently applied. In addition, a wide range of symptom severity and functional impairment is captured by the current case definitions. The proportion of Gulf War-deployed Veterans who meet case criteria for GWI is approximately 34% (based on the Kansas case definition) to as high as 60% (based on the less-restrictive CDC case definition).^16^ While the etiology of GWI is still debated, as many as 250,000 former service members may suffer from GWI,^17^ making the need for treatment urgent.

Identification and treatment of GWI is a top research priority for the VA Office of Research and Development (ORD). Although the VA and DoD developed an evidence-based clinical practice guideline for the management of CMI in 2014,^18^ only 3 of the identified trials investigated treatment of GWI specifically (other CMI conditions reviewed included chronic fatigue syndrome, irritable bowel syndrome, and fibromyalgia, and included non-Veteran populations). The VA and other institutions have recently provided funding for numerous trials of treatments and management strategies for GWI, and the research in this area is rapidly expanding. An updated, systematic evidence review that focuses on the treatment of GWI in Gulf War Veterans is needed to understand this emerging body of evidence and assist Veterans Health Administration (VHA) leadership in developing and funding future clinical and research priorities.

This systematic review seeks to expand on recent work by identifying potentially promising interventions for the treatment of GWI and its related symptoms as well as identifying any areas that have been relatively well-studied and shown to be ineffective or harmful. Together, this will help target resources for further inquiry.