# Executive Summary

## Aim

We conducted a systematic review to evaluate the effectiveness and harms associated with therapeutic interventions for Gulf War Illness (GWI) and its related symptoms. This review helps to identify treatments that warrant further inquiry, as well as treatments with a moderate base of evidence showing lack of effect and potential for harm.

## Methods

We searched electronic databases, clinical trial registries, and reference lists through September 2019 for randomized and non-randomized controlled trials (RCT/nRCT) and cohort studies directly comparing interventions for Veterans with GWI to each other, placebo, or usual care. We excluded studies that compared interventions in Veterans without GWI to those with GWI, unless there was a separate analysis of the comparison in only those with GWI. We also excluded non-comparative studies except when summarizing emerging research. We abstracted data on study design, demographics, interventions, and outcomes. Two reviewers independently assessed studies’ full text for inclusion, quality (risk of bias [ROB]), and strength of evidence (SOE) using published criteria and resolved discordant ratings by discussion and consensus.

## Results

We identified and synthesized the evidence from 12 RCTs, each of which examined a different intervention for GWI (Figure i). We found several promising – but not definitive – treatments for various symptoms associated with GWI. We found moderate-strength evidence that cognitive behavioral therapy (CBT), exercise, and the combination of the 2 were associated with improvements in several GWI symptom domains. We found low-strength evidence that the following interventions improved 1 or more outcomes in patients with GWI:

- Mindfulness-based stress reduction (MBSR) improved^*^ pain, cognitive functioning, fatigue, depression, and posttraumatic stress disorder (PTSD).
- Mind-body bridging (MBB) – another type of mindfulness intervention – improved^*^ fatigue, depression, PTSD, and sleep, though it did not improve overall physical or mental health, pain, or cognitive functioning.
- Continuous Positive Airway Pressure (CPAP) improved^*^ overall physical health, pain, cognitive functioning, fatigue, mental health, and sleep quality in a small study of Veterans with sleep-disordered breathing and GWI.

We found moderate-strength evidence that doxycycline is ineffective for GWI in mycoplasma DNA-positive Veterans and increases the risk of adverse effects compared with placebo. We found no effects of treatment with mifepristone, naltrexone, or rifaximin on GWI-associated symptoms, and some indications of benefit with carnosine, Coenzyme Q_10_ (CoQ10), acupuncture, and detoxification, though the SOE for these findings was insufficient to draw conclusions due to methodical limitations of the studies. No studies examined the effects of interventions on respiratory or dermatologic outcomes.

Most of this evidence base consists of small studies each examining a different intervention, and the findings described are likely to change as more research is conducted. We identified 31 ongoing or unpublished studies, 2 published single-arm studies, and 2 studies that were terminated prior to completion. Few of these ongoing studies examine an intervention that has previously been studied: 2 of cognitive behavioral approaches, 1 of MBSR, and 1 with an acupuncture component. Aside from 2 ongoing studies examining forms of transcranial direct current stimulation (tDCS), and 3 examining repetitive transcranial magnetic stimulation (rTMS), no 2 ongoing studies address the same intervention, and the interventions examined by the remaining 22 studies vary widely.

Figure i Summary of findings

Treatment; Subpopulation if applicable | Outcome domain
Treatment; Subpopulation if applicable | Physical health overall | Pain | Cognitive | Fatigue | Mental health overall | Depression | Global outcomes (function, QoL) | PTSD symptoms | Sleep | GI symptoms | Adverse events
Medications vs placebo
Doxycycline^1^; Positive mycoplasma | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | ★★
Mifepristone^2^ | Ø | --- | Ø | Ø | Ø | Ø | --- | Ø | --- | --- | Ø
Naltrexone^3^ | Ø | --- | Ø | --- | --- | --- | --- | --- | --- | --- | Ø
Rifaximin^4^; IBS (Rome III) | --- | --- | --- | --- | --- | --- | Ø | --- | --- | Ø | Ø
Nutritional supplements vs placebo
Carnosine^5^ | --- | Ø | Ø | Ø | --- | --- | --- | --- | --- | Ø | Ø
CoQ10^6^ | Ø | --- | Ø | --- | --- | --- | --- | --- | --- | --- | Ø
Psychological, exercise, or multi-component interventions
CBT^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
Exercise^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
CBT + Exercise in combination^a^,^7^ | ★★ | ★★ | ★★ | ★★ | ★★ | --- | --- | --- | --- | --- | Ø
Detox regimen^b^,^8^ | Ø | Ø | --- | Ø | Ø | --- | Ø | --- | --- | --- | Ø
Mindfulness-based stress reduction^b^,^9^ | --- | ★ | ★ | ★ | --- | ★ | --- | ★ | --- | --- | ---
Sleep focused mind-body bridging^c^,^10^ | Ø | Ø | Ø | ★ | Ø | ★ | Ø | ★ | ★ | --- | ---
Other interventions
Acupuncture^a^,^11^ | Ø | Ø | --- | --- | --- | --- | --- | --- | --- | --- | Ø
CPAP^d^,^12^ | ★ | ★ | ★ | ★ | ★ | --- | --- | --- | ★ | --- | ---

Shading represents the direction of effect: Pale yellow=Mixed Findings/Unclear, Green=Evidence of benefit, Gray=No association, Red=Favors usual care

Symbols represent the strength of the evidence: --- No evidence, Ø Insufficient, ★Low, ★★ Moderate, ★★★ High

a Versus usual care/TAU

b Versus waitlist

c Versus sleep education

d Versus sham CPAP

## Conclusion

We found a small but growing body of evidence examining a disparate array of treatments for Veterans with GWI. There is low- to moderate-strength evidence that suggests several treatments may hold promise for improving symptoms related to GWI: the evidence was moderate-strength for benefits of a combination of CBT and exercise and low-strength for 2 distinct mindfulness-based interventions and CPAP for Veterans with GWI who have sleep-disordered breathing. Doxycycline, on the other hand, is likely to be an ineffective treatment and is associated with harms (moderate-strength evidence). There are 33 ongoing, single-arm pilot, or unpublished studies examining a variety of interventions: some of these studies will help strengthen the evidence base for interventions that have already been examined on a small scale (eg, CBT and mindfulness-based stress reduction). However, many of these studies examine interventions that are both different from each other and different from interventions that have been studied before. While this approach may help identify potentially promising interventions, the variety of treatments examined will make it challenging to develop enough of an evidence base to guide clinicians about which treatments are most likely to be effective in clinical practice and which treatments should be avoided. Part of the challenge in studying treatment of GWI is the lack of an agreed-upon case definition, and the heterogeneity of symptoms and differing degrees of functional impairment experienced by those with GWI. Addressing these issues will help researchers to better target intervention-focused research.

## Abbreviations Table

Abbreviation: Definition
A: Actual
AA: African American
AMED: Allied and Complementary Medicine Database
BAC-A: Brief Assessment Checklist for Adolescents
BDI: Beck Depression Inventory
BID: bis in die
BPI: Brief Pain Inventory
BPI-SF: Brief Pain Inventory-Short Form
BSI: Brief Symptom Inventory
BSS: Bowel Symptom Scale
BVMT-R: Brief Visuospatial Memory Test-Revised
CAPS-5: Clinician-Administered PTSD Scale for DSM-5
CBC: Complete Blood Count
CBT: Cognitive Behavioral Therapy
CBTi: Cognitive Behavioral Therapy for Insomnia
CCRCT: Cochrane Central Register of Controlled Trials
CDC: Centers for Disease Control and Prevention
CDMRP: Congressionally Directed Medical Research Programs
CDSMP: Chronic Disease Self-Management Program
CDSR: Cochrane Database of Systematic Reviews
CES-D: Center for Epidemiological Studies-Depression Scale
CFQ: Cognitive Failures Questionnaire
CFQ11: Chalder Fatigue Scale
CFS: Chronic Fatigue Syndrome
CI: Confidence Interval
CINAHL: Cumulative Index to Nursing and Allied Health Literature
CMI: Chronic Multisymptom Illness
CoE: Center of Excellence for Research on Returning War Veterans
CoQ10: Coenzyme Q_10_
COWAT: Controlled Oral Word Association Test
CPAP: Continuous Positive Airway Pressure
CPT: Connors Continuous Performance Test
CPT-3: Conner’s Continuous Performance Test - 3rd Edition
CRS: Chronic Rhinosinusitis
CVLT-II: California Verbal Learning Test Second Edition
DB-RCT: Double-Blind Randomized Controlled Trial
DCS: D-cycloserine
D-KEF: Delis-Kaplan Executive Function System
DoD: Department of Defense
DTI: Diffusion Tensor Imaging
DTS: Davidson Trauma Scale
E: Estimated
EBM: Evidence-based Medicine
EEG: Electroencephalogram
AE: Adverse event
EHR: Electronic health record
EMG: Electromyography
ERP: Event Related Potential
ESP: Evidence Synthesis Program
f: Cohen’s f Value
FIQR: Revised Fibromyalgia Impact Questionnaire
FIT: Rey 15-Item Test
FODMAP: Fermentable Oligo-, Di-, Mono-saccharides And Polyols
FSS: Fatigue Severity Scale
GAD-7: Generalized Anxiety Disorder 7-item
GI: Gastrointestinal
GW: Gulf War
GWHE: Gulf War Health Education
GWI: Gulf War Illness
GWV: Gulf War Veteran
GWVI: Gulf War Veterans Illness
HA: Headache
HADS: Hospital Anxiety and Depression Scale
HAM-A: Hamilton Anxiety Rating Scale
HAM-D: Hamilton Depression Rating Scale
HD-tDCS: High Definition transcranial Direct Current Stimulation
HIT-6: Headache Impact Test
HPG: Hypothalamic-Pituitary-Gonadal
HPT: Hypothalamic–Pituitary–Thyroid
HRQoL: Health-Related Quality of Life
HVLT-R: Hopkins Verbal Learning Test – Revised
IBS: Irritable Bowel Syndrome
IBS-QoL: Irritable Bowel Syndrome Quality of Life
ICTRP: International Clinical Trials Registry Platform
IQR: Interquartile Range
ISI: Insomnia Severity Index
LDLPFC: Left Dorsolateral Prefrontal Cortex
LED: Light Emitting Diode
LMC: Left Motor Cortex
MA: Meta-Analysis
MAP: Mean Arterial Pressure
MASQ: Mood and Anxiety Symptoms Questionnaire
MATRICS: Measurement and Treatment Research to Improve Cognition in Schizophrenia
MBB: Mind-Body Bridging
MBSR: Mindfulness-based Stress Reduction
MCS: Mental Component Summary
MFI-20: Multidimensional Fatigue Inventory-20
MFSI: Multidimensional Fatigue Symptom Inventory
MPI: Multidimensional Pain Inventory
MPQ: McGill Pain Questionnaire
MRI: Magnetic Resonance Imaging
MRS: Magnetic Resonance Spectroscopy
MSG: Monosodium glutamate
NI: Nasal Irrigation
NR: Not Reported
NRCT: non-Randomized Controlled Trial
NSI: Neurobehavioral Symptom Inventory
ORD: Office of Research and Development
P: P-Value
PCL: PTSD Checklist
PCS: Physical Component Summary
PDI: Pain Disability Index
PFS: Piper Fatigue Scale
PHQ: Patient Health Questionnaire
PICOTS: Population, interventions, comparators, outcomes, timing, and setting
preSMA: Presupplementary Motor Area
PRESS: Peer Review of Search Strategies
PROMIS: Patient Reported Outcomes Measurement Information System
PSQI: Pittsburgh Sleep Quality Index
PSS-I: PTSD Symptom Score interview
pts: Participants
PTSD: Post-Traumatic Stress Disorder
QoL: Quality of Life
RCT: Randomized Controlled Trial
ROB: Risk of Bias
rTMS: Repetitive Transcranial Magnetic Stimulation
SAT: Symptoms Assessment Tool
SCL-90R: Symptom Checklist-90-Revised
SD: Standard Deviation
SE: Standard Error
SED: Sleep Education
SF-12V: Standard Form 12-Veteran version
SF-36: 36-Item Short Form Health Survey
SF-MPQ: Short-Form McGill Pain Questionnaire
SNOT-20: Sinonasal Outcome Test-20
SOE: Strength of Evidence
SORT: Semantic Object Retrieval Test
SR: Systematic Review
TAU: Treatment as Usual
tDCS: Transcranial Direct Current Stimulation
TEP: Technical Expert Panel
TMT: Trail Making Test
Tx: Treatment
USA: United States of America
VA: Veterans Affairs
VAMC: Veterans Affairs Medical Center
VAS: Visual Analog Scale
VHA: Veterans Health Administration
VNS: Vagus Nerve Stimulation
VSF-36: Veterans 36-Item Short Form
VSL: Very Safe Lactobacilli
WAIS-IV: Wechsler Adult Intelligence Scale-Fourth Edition
WHO: World Health Organization
WHODAS: World Health Organization Disability Assessment Schedule
WRIISC: War Related Illness and Injury Study Center

* Specifics on improvement for these outcomes are defined in the subsequent full report