# APPENDIX E Peer Review Comments/Author Responses

# | Reviewer Comment | ESP response
Are the objectives, scope, and methods for this review clearly described?
1 | Yes
2 | No - yes they are in sufficient detail
3 | Yes
4 | Yes
5 | Yes
6 | Yes
8 | Yes
Is there any indication of bias in our synthesis of the evidence?
1 | No
2 | No
3 | No
4 | No
5 | Yes - the review seems to be done fairly, and in an unbiased way
6 | No
8 | No
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
1 | No
2 | No
3 | No
4 | No
5 | No
6 | No
8 | Yes - Maybe, please see comments in attached review.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
1 | This systematic review of interventions for Gulf War Illness (GWI) was reasonably well done and is timely given the ongoing interest and need for improved management of GWI. I have no concerns or critique of the actual systematic review itself (procedures and write-up) but do have two major concerns, one methodological and the other is more philosophical.; First, philosophically I think this review is probably premature. Mainly, because a clinical definition of what GWI remains elusive and there is no consensus or diagnostic definition. As a consequence, this review is really nothing more than a review some treatments for diseases that may (or may not) be part of a more “global” disease/disorder that we refer to as GWI. Until such time that we get to consensus agreement on exactly what GWI is and what diseases/disorders/symptoms define GWI we doing nothing more than “guessing” about managing GWI by using treatments for specific diseases/disorders that we “believe” are part of GWI and may have shown efficacy in the past, and hoping that they work similarly in those we define as GWI by the CDC/Kansas definition. | We agree that there are many challenges inherent in the study of an illness that is poorly defined. We do cite some of these limitations in the discussion section. Our hope and goal was to identify treatments that might be promising and worthy of further inquiry as well as identify treatments that may be ineffective or harmful. We have modified our aim to clarify this point.
1 | Which brings me to my second major concern. In the Executive Summary (pg. 1) and in the “Study Section” (pg. 10) you state that: “We excluded studies that compared interventions in Veterans with versus those without GWI.”. I believe that exclusion of these types of studies is a catastrophic limitation to this report for several reasons. One, relates to the concern raised above in that, since we do not have a clinical definition/criteria to define/diagnose GWI (other than CDC & Kansas criteria) we really do not know what we are dealing with. Thus, the treatments evaluated are not treatments for GWI, but rather for specific other diseases/disorders that may, or may not, be part of the GWI. It would have been inherently interesting and informative to have included studies that compared GWI versus no GWI. If for example, those designated as GWI (by CDC/Kansas) failed to show a favorable response to CBT or CPAP compared to those without GWI would suggest that simply using existing treatments/interventions for the symptom domains of GWI is not effective and that at present we have a great deal of work yet to do to develop treatments/interventions in and for GWI. By not including the non-GWI comparative studies we have limited information as to whether the treatments/interventions evaluated in this review work as well for the target disorder/symptom domain in those with GWI. | All of the studies compared treatment and placebo in a cohort of Veterans who were identified to have GWI. We did not exclude any studies for including a population other than GWI (and we were open to the possibility of including such as study had they met all of our other inclusion criteria e.g., also included a control group with GWI). We have revised the Study Selection section to be clear that we would have included studies that compare the same intervention in GWI and another illness as long as that study also had a control treatment had we found any.
1 | Since one of the purposes of this type of review is to summarize a literature with aim of providing some clinical guidance regarding best practice. That aim was not achieved, in part due to the wide variability in the science, lack of a consensus clinical definition of GWI, and exclusion of studies that employed non-GWI comparison group. Until such time that a clinical diagnostic criteria is ratified, the within and between groups variability will never afford the stability necessary to generate meaningful information from systematic reviews. | We agree that there are many challenges inherent in the study (and evidence synthesis) of an illness that is poorly defined. We do cite some of these limitations in the discussion section. We clarify that our aim was not to characterize literature in the spirit of developing treatment guidelines, rather we sought to identify treatments that might be promising and worthy of further inquiry as well as to identify treatments that may be ineffective or harmful. This would help streamline future resources to build an evidence base to develop clinical guidelines. The use of the report would be up to the stakeholders.
1 | Research with an emphasis on defining GWI is paramount. Fortunately, there are two such studies, currently in their first year, underway. One is using a comprehensive chart review process to better understand the clinical manifestations in those with presumed GWI and the other is employing a “machine learning” approach mining VHA healthcare data to try and identify clusters of healthcare data that may correlate with clinical classifications of GWI. | Thank you for this information. We have now specifically referenced these ongoing studies in the discussion section.
1 | This systematic review was done with rigor and is well written however, for the reasons noted above, I believe it is premature and offers clinicians little with regard to management of their patients with believed to be suffering with GWI. | Thank you, we have clarified in our Aims that our goal was not to develop clinical guidelines rather to review current evidence to (1) identify treatments that might be promising and worthy of further inquiry and (2) identify treatments that may be ineffective or harmful.
2 | This is extremely well done and will prove very valuable. I have no concerns. While there may be other studies out there, they are not of major importance or relevance. | Noted, thank you.
3 | Thank you for the opportunity to review this evidence based synthesis. I read this over a few times and had very few comments. This was excellently done, easy to read and clear. Thank you.; I had one main comment. I think the reviewers should include information on adherence. Adherence to these treatments were generally low. I know that this wasn’t a primary purpose of the study – but it would be easy to include it in the tables and I think it would be informative. If a Veteran won’t use the treatment, this is important to know. | We agree this is important, especially when considering feasibility of patient engagement in psychosocial and exercise interventions that are time intensive. We have now added information about adherence for all studies that reported it.
3 | Minor comment: First table – what does PTSD mean in the label for the table under mindfulness? | This was originally to display a subpopulation that was examined in the study, we have removed it to reduce confusion.
4 | I think that this is an excellent review. Well done. | Thank you.
4 | Page 25: I would comment on the Study of Amin et al. on the use of CPAP in GWI and sleep disordered breathing. DOI 10.1007/s11325-010-0406-8.(12) This study of GWI and sleep disordered breathing (SDB) appears to confirm the effectiveness of nasal CPAP in treating the symptoms of SDB and obstructive sleep apnea. According to the AASM criteria, as listed in the International Classification of Sleep Disorders: Diagnostic and Coding Manual, Second Edition. At least 1 of the following criteria must apply for obstructive sleep apnea (OSA) to be diagnosed:; - The patient reports daytime sleepiness, unrefreshing sleep, fatigue, insomnia, and/or unintentional sleep episodes during wakefulness. The patient awakens with breath holding, gasping, or choking. The patient’s bed partner reports loud snoring, breathing interruptions, or both during the patient’s sleep.; - Polysomnography (PSG) shows more than 5 scoreable respiratory events (eg, apneas, hypopneas, RERAs) per hour of sleep and/or evidence of respiratory effort during all or a portion of each respiratory event.; - PSG shows more than 15 scorable respiratory events (eg, apneas, hypopneas, RERAs) per hour of sleep and/or evidence of respiratory effort during all or a portion of each respiratory event.; - Another current sleep disorder, medical or neurologic disorder, medication use, or substance use does not better account for the patient’s condition.; Many of the GW Veterans included in this study fit the OSA criteria; it is not a surprise that symptoms improved with CPAP.; I don’t think this study adds valuable knowledge about treatment of GWI. This study uses an evidence-based intervention, CPAP, to treat SDB/OSA. The patients in this study had symptoms that were readily attributed to a diagnosable condition other than to GWI, that is OSA. I think your review should provide this information in your discussion of the study results. It is a source of bias in the study. | This is a valid point. CPAP is an evidence-based treatment used to treat sleep apnea. The patients in the study all had sleep-disordered breathing in addition to GWI. We think this intervention is important to include because the study found improvement in broader range of GWI symptoms (not just sleep outcomes) with CPAP treatment. It therefore may be worthwhile for clinicians to determine whether Veterans with GWI have sleep-disordered breathing and use a CPAP to address both sleep disordered breathing as well as a broader range of GWI symptoms.
5 | Overall I found the Evidence Synthesis Program to be a very well organized review of a complex literature. I think it will be a valuable resource for those working in the field of Gulf War Illness. Specific comments follow; | Thank you. See responses below.
5 | p. 23 line 11: typo “delivered a in 8 weekly…” should read “delivered in 8 weekly…” | Corrected.
5 | p.23, line 41 states that participants used self-reported outcomes without blinding of participants. Since blinding of participants is not possible in psychological and exercise interventions, I suggest clarifying the statement to say this. | The role and necessity of patient blinding in studies of these types of interventions has been debated. There are techniques even for complex nonpharmacologic interventions to blind patients to some degree. Some argue that lack of patient blinding in trials of non-pharmacologic therapies may considerably exaggerate treatment effects; in which case, it would be difficult to determine whether and to what extent positive treatment effects – especially for the findings with only low level confidence – were due to an independent effect of treatment, expectancy as a mechanism of change, placebo effect, or a combination of these factors. On the other hand, others have argued that blinding is not only challenging but also potentially counterproductive as expectancy for change is thought to be an integral part of the intervention itself. We have added this to the discussion.
5 | p. 29, line 35 describes the study done by my group (I am the P.I.). The manuscript giving details of the study and the results is still under peer review, and is described in the Evidence Synthesis Program using ref #37 (clinicaltrials.gov identifier) and ref #58 (an abstract). The information from these references is incomplete. I don’t know if the manuscripts will be excepted for puplication before the Evidence Synthesis Program is published, here is the reference for the manuscript currently under review.; Bayley, P. J., Cho, R. Schulz-Heik, R. J., Mathersul, D. C., Collery L., Shankar, K. Ashford, J. W. Jennings, J. Tang, J. Wong, M. Avery, T. J. Stanton, M. Meyer, H. Friedman, M. Kim, S. Jo, B. Younger, J. Mathews B., Majmundar M. & Mahoney L. Yoga is effective in treating symptoms of gulf war illness: a randomized clinical trial (in review).; I do not want to list all the results in the paper before it is published, but you may want to cite it (e.g., p.29, in the paragraph starting on line 35). For accuracy, I suggest making the following edits to the existing text;; i. The comparator group in the study is more accurately described as CBT. I recommend changing Table 7 the comparator group from a “pain management wellness group” to “CBT”. Similarly, p.29, line 35 should refer to a “CBT” group rather than a “CBT-based pain management wellness group for pain”. Similarly, p. 69 line 24–25 “pain management wellness group” should be changed to “CBT”; ii. the study used the CDC GWI case definition, so I suggest changing p.68, line 56 from “not specified” to “CDC” | We have made these changes as suggested.
5 | p. 33, line 45 refers to publication #4 as “a narrative review of …GWI research”. It doesn’t look like a review to me, and the abstract calls it “a double-blind, placebo-controlled study”. | Thank you, that citation was incorrect. We have replaced it with the correct citation: Chester JE, Rowneki M, Van Doren W, Helmer DA. Progression of intervention-focused research for Gulf War illness. Mil Med Res. 2019;6(1):31 31627737 .
5 | The Summary Table (p.36–37) describes the results from a large RCT by Donta et al (2003). The table shows the results for the CBT (line 54) and CBT + Exercise (line 56) interventions, coded to show evidence of benefit for pain. I am not sure this is accurate. Donta et al stated that “only 1 of the 4 measures of pain (affective) showed significant treatment differences for CBT alone and CBT plus exercise compared with usual care” As a result, Donta et al state several times that “neither treatment had a significant impact on pain” (Abstract, Comment). In my opinion, it would be more accurate to recode the findings for pain in this study to be either Mixed/Unclear (which would then match how they are reported in Table 5), or even No Benefit. | Thank you for pointing out this discrepancy between tables. We meant for it to be mixed/unclear findings for CBT and CBT+Exercise for pain and have updated the summary table to reflect this.
8 | Overall, this manuscript provides a comprehensive National overview of published and currently active Gulf War studies with focus on treatments and therapeutics. Inclusion of Risk of Bias (ROB), Strength of Evidence (SOE), and discussion of studies focused on GWI vs. symptoms of GWI are strengths of this review.; This manuscript will no doubt provide important Gulf War field-forward objectives and guidance for investigators and funding agencies. | Noted, thank you.
8 | Could the authors include a paragraph or discussion of a Standard Operation Procedure (SOP) or an outline of how clinical trials should be experimentally and methodologically assembled for subsequent good synthesis review? This could be a nice value added to this manuscript as VA often contracts with NASEM and inclusion of studies are important for overall interpretation. | This is a very important point, but it is beyond the scope of this report. We have asked the ESP Coordinating Center to examine this issue and have had follow up correspondence about a plan to help develop some guidance about this. We also include in our discussion very broad points about future research needs and approaches, but these are by no means comprehensive.
8 | Could the authors include a discussion of literature not included in the ESP that maybe a promising treatment on the horizon if the experimental approach were solid. | Unfortunately, for the systematic review, we are only able to include literature captured by our search and that meets our inclusion criteria. Key Question 3 does capture ongoing studies of treatments, but anything beyond that is outside the scope of this review.
8 | Executive Summary (pg1); …We excluded studies that compared interventions in Veterans with versus without GWI… why? Were there treated and untreated numbers in each group? If so, wouldn’t that include GWI Veterans with and without treatment? | We have clarified that this exclusion would only be in the case where both treated and untreated groups contained GWI and non-GWI participants, and there was no separate analysis. However, no studies were excluded for this reason.
8 | Executive Summary (pg1): Were there any nRCTs in the literature and considered or not for evidence synthesis? | The study design was allowed, but none met our inclusion criteria, with the exception of one ongoing study on acupressure (see Table 13).
8 | Executive Summary (pg1); MBSR, MBB, and CPAP results: “improved” outcomes including fatigue, depression, PTSD, pain cognitive, and sleep. How was improved defined? Was this a qualitative conclusion by the authors or was it based on objective quantitative measures? | We are trying to be brief in the Executive Summary, but we have added a footnote referring readers to the full report for how improvement was defined in the relevant studies.
8 | Abbreviations Table (pg4) Please add:; - AE = Adverse Effect; - PICOTS = ?; - SOE = Strength of Evidence | We have made the suggested changes.
8 | Evidence Report (pg8); Introduction:; - Add symptoms within 6-month deployment were applicable | We have added this in the introduction.
8 | Methods (pg9) Figure 1. Conceptual Framework; We may need to tweak this figure. Suggestions:; - Remove “case definition” under Patient Subgroups. There is no clinical case definition.; - Remove “case definition” under Veterans with GWI. Include: … and meet inclusion/exclusion criteria based on the instrument. | Thank you, we have made this change to the Figure 1.
8 | Study Selection (pg10): We excluded studies that compared interventions in Veterans with versus Veterans without GWI: How many studies were excluded? | We did not count how many were excluded for this exact reason, but they would fall under “excluded populations” in our full text review (see literature flow diagram). Since there were 5 exclusions for population, there are 5 or less studies that were excluded for this reason.
8 | Table 1 PICOTS by Key Question (pg 11): Key Question (KQ2 – hard to understand based on current wording. Please rephrase. | We have edited the wording of the question for clarity.
8 | Data Abstraction, Quality Assessment (pg12): In lieu of “investigator” or reviewer(s), Consider changing to ESP-reviewing member or ESP-reviewer where applicable. | We have made this change.
8 | Quality Assessment: ROB should be on the first sentence, not sentence 2. | Correction made.
8 | Table 3. (pg21). Table 4 (pg22): Remove ROB after low, high. | Correction made.

# = anonymous reviewer number