# APPENDIX D Data Supplement

Table 9 Results for physical health, pain, and fatigue outcomes in intervention trials for Gulf War Illness

Intervention and study characteristics^a^ | Physical Health Overall | Pain | Fatigue
Medications
Doxycycline^1^ (n=245) vs placebo (n=246); Total N=491; Subpopulation: positive mycoplasma DNA test; Tx duration: 12 months; Observation: 18 months; ROB: Low | Veterans SF-36 PCS Pt score; N analyzed: 199 vs 212; Least-square mean difference (95% CI; Tx minus C) at 12 months: 1.0 (−0.3 to 2.4), P=0.12 | McGill Pain Questionnaire (N analyzed), least-square mean difference (95% CI; Tx minus C) at 12 months:; Sensory (207 vs 214): −0.6 (−1.8 to 0.6), P > 0.2; Affective (206 vs 214): 0.0 (−0.5 to 0.5), P > 0.2; Pain now (207 vs 213): −0.3 (−0.7 to 0.1), P=0.18; Typical pain (206 vs 213): 0.0 (−0.4 to 0.3), P > 0.2 | MFI (N analyzed), least-square mean difference (95% CI; Tx minus C) at 12 months:; General fatigue (206 vs 214): −0.1 (−0.7 to 0.5), P > 0.2; Physical fatigue (206 vs 214): −0.1 (−0.6 to 0.5), P > 0.2; Reduced activity (207 vs 214): 0.0 (−0.6 to 0.7), P > 0.2; Reduced motivation (206 vs 214): −0.2 (−0.8 to 0.4), P > 0.2; Mental fatigue (206 vs 213): 0.0 (−0.6 to 0.6), P > 0.2
Mifepristone^2^ (n=18 in each phase 1 and 2) vs placebo (n=18 in phase 1, n=15 in phase 2), 6-week crossover phases, 1m washout; Phase 1 Total N=36; Phase 2 Total N=33; Tx duration: 6 weeks; Observation: 4 months; ROB: Some concerns | Veterans SF-36 (acute form) PCS score: Mifepristone treatment was not associated with improvement in self-reported physical health status (p=0.838); Overall mean change, ΔT minus ΔC (SD): −0.46 (7.76), P=0.738 | NR | General fatigue (MFI-20) Overall mean change, ΔT minus ΔC (SD): 0.63 (3.37), P=0.302
Naltrexone^3^ vs placebo (n’s=NR), crossover phases separated by 1-month washout.; Total N=40; Tx duration: 3 months; Observation: 7 months; ROB: High | Change in CGIS favored naltrexone: 14 (35%); Change in CGIS favored placebo: 5 (12.5%); No change from baseline: 18 (45%); (Tx vs C not significant) | NR | NR
Nutritional supplements
Carnosine^5^ (n=12 finished study) vs placebo (n=13 finished study); Total N=34; Tx duration: 12 weeks; Observation: 14 weeks; ROB: High | NR | No changes in average (dolorimetry) pain thresholds, and no differences between groups. | CFS severity score: no differences between groups.; Instantaneous fatigue scores: no treatment effects.
CoQ10 ^6^; 100 mg/d (n=11) vs 300 mg/d (n=12) vs placebo (n=23); Total N=46; Tx duration: 3.5 +/− 0.5 months; Observation: 3.5 +/− 0.5 months; ROB: High | GSRH: improved from baseline (threshold not defined for improved/not improved):; Q100 (N=10) vs placebo (N=19): OR (95% CI):; All Pts (N=46): 1.88 (0.26 to 13.4), P=0.53; Physical function assessed by Summary Performance Score:; Q100 vs Placebo, % Pts Improved from baseline: 82% vs 40%; Absolute difference: 42% (P=0.025). Women contributed to this benefit.; Q300 vs Placebo, % Pts Improved from baseline: 55% vs 40%; Absolute difference: 15% (P=0.44).; SPS improvement on Q300 was not significant, though the effect on Q100 did not differ significantly from that on Q300 (P=0.17). | NR | NR
Psychological, exercise, or multi-component interventions
CBT+Exercise^7^ (n=266) vs CBT (n=286) vs Exercise (n=265) vs TAU (n=270); Total N=1092; Tx duration: 12 weeks; Observation: 12 months; ROB: Some concerns | VSF-36 PCS Score: % of Pts with 7+ points improvement vs baseline at 3 months, 6 months, 12 months:; CBT + exercise (n=266): 16.5, 16.2, 18.4; CBT alone (n=286): 15.0, 12.9, 18.5; Exercise alone (n=265): 12.8, 13.6, 11.7; TAU (n=270): 9.3. 12.2, 11.5; OR (95%CI) for 7+ points PCS improvement vs TAU, adjusted for study design, pending disability claims, and baseline V/SF-36 physical component summary score:; Exercise: 1.07 (0.63 to 1.82); CBT: 1.72 (0.91 to 3.23); Exercise + CBT: 1.84 (0.95 to 3.55); Overall (marginal) effect, OR (95%CI) for 7+ points PCS improvement vs TAU:; CBT (n=552) vs no CBT (n=535): 1.71 (95% CI, 1.15 to 2.53); Exercise (n=531) vs no exercise (n=556): 1.07 (95% CI, 0.76–1.50) | MPQ-S: Of the 4 subscales: sensory, affective, pain right now, typical level of pain, affective pain was significantly reduced (P < 0.025) vs TAU in CBT arms:; CBT alone: −0.43; CBT + Exercise: −0.50; All other findings not significant. | MFI: Both exercise arms (exercise, CBT+Exercise) significantly improved fatigue (P < 0.05) vs TAU on all 5 domains (general, physical, reduced activity, reduced motivation, mental fatigue).; CBT alone: No significant changes from baseline on any of the 5 MFI domains.
Detox regimen^8^ (n=22) vs waitlist (n=10); Total N=32; Tx duration: 4–6 weeks; Observation: 3 months; ROB: Some concerns | VF-36 PCS: Difference in score (95% CI) between Waitlist and Tx at Week 6, adjusted for baseline (Positive changes indicate improvement): 6.9 (−0.3 to 14.2); P=0.06 Subscales of VF-36 physical:; Physical functioning : 2.7 (−18.1 to 23.5) P=0.8; Role-physical: 27.6 (6.9, to 48.3) P=0.009; General health: 20.7 (9.2 to 32.3) P < 0.001; Vitality: 31.2 (15.6 to 46.9) P < 0.001 | MPQ-2-SF: Difference in score (95% CI) between Waitlist and Tx at Week 6, adjusted for baseline (Negative changes indicate improvement):; Total pain score: −1.1 (−2.0 to −0.2); P=0.02.; VR-36 bodily pain subscale score: 26.4 (8.5, 44.4) P=0.004 | MFI: Difference in score (95% CI) between Waitlist and Tx at Week 6, adjusted for baseline (Negative changes indicate improvement):; General fatigue: −4.3 (−7.4 to −1.3); P=0.006; Physical fatigue: −3.5 (−6.9 to −0.2); P=0.04; Reduced activity: −4.0 (−7.3 to −0.7); P=0.02; Reduced motivation: −3.1 (−5.6 to −0.5); P=0.02; Mental fatigue: −5.7 (−8.7 to −2.7); P < 0.001
Mindfulness-based stress reduction^9^ (n=26) vs TAU (n=29); Total N=55; Tx duration: 8 weeks; Observation: 6 months; ROB: Some concerns | NR | MPQ-2: Tx group reported greater reductions in pain at 6 months compared to TAU:; Post-treatment: f=0.13; P=.45; 6 months: f=0.33; P=.05 | MFI General Fatigue:; Tx group reported significant improvement in fatigue at 6 months compared to TAU:; Post-treatment: f=0.18; P=0.27; 6 months: f=0.32; P=0.03; PROMIS fatigue: significant improvement with Tx vs TAU at both timepoints:; Post-treatment: f=0.35; P=0.02; 6 months: f=0.26; P=0.05
Sleep focused mind-body bridging^10^ (n=33) vs sleep education (n=27); Subpopulation: sleep disturbance; Total N=60; Tx duration: 3 sessions over 3 weeks; Observation: 3 months; ROB: Some concerns | PA-assessed physical condition (N (%) improved): 8 (32%) vs 3 (13.6%); P=NS | QoL (SF-36 pain):; Pre: 38.9 (30.8–47.0) vs 37.9 (29.5–46.2); Post: 46.6 (37.9–55.4) vs 39.1 (30.0–48.3); Observation: 45.0 (36.6–53.5) vs 39.5 (28.6–50.4) | Post-randomization treatment by period interaction: effect size 0.47 (P=0.032). The 2 interventions differed at Observation (p=.052), in which improvement in mental fatigue for MBB (1.99) was greater than that for SED (.36), from the baseline covariate (17.74). MFI, unadjusted mean (95% CI):; General fatigue:; Pre: 21.0 (20.1 to 21.9) vs 20.7 (19.3 to 22.0); Post: 19.4 (18.1 to 20.8) vs 20.0 (18.7 to 21.3); Observation: 18.8 (17.3–20.4) vs 20.2 (18.4–22.0); Mental fatigue:; Pre: 18.3 (17.2 to 19.5) vs 17.4 (15.9 to 18.9); Post: 16.2 (14.7 to 17.7) vs 16.2 (14.5 to 17.9); Observation: 16.1 (14.5 to 17.7) vs 17.1 (15.4 to 18.8)
Other interventions
Acupuncture^11^ 2x/week (n=52) vs 2-month waitlist then acupuncture 1x/week (n=52); Total N=104; Tx duration: 6 months; Observation: 6 months; ROB: Some concerns | SF-36P significantly improved by mean 9.4 points with T vs waitlisted group at month 6, adjusted for baseline pain. (P=0.03). | MPQ: at 6 months, treatment group had an average reduction of 3.6 points (p=0.04) compared to the comparator group. | NR
CPAP^12^ (n=9) vs sham CPAP (n=9); Subpopulation: sleep-disordered breathing; Total N=18; Tx duration: 3 weeks; Observation: 3 weeks; ROB: Low | Treatment group experienced 34% improvement in physical health.; SF-36 PCS: between groups effect size 2.79 (P=0.0003); Correlation with sleep stage shifts: −0.41 (P=0.104) | Treatment group experienced 34% reduction in pain.; Pain VAS (0–10, daily): between groups effect size 2.14 (P=0.0008); Correlation with sleep stage shifts: 0.51 (P=0.037) | Treatment group experienced 38% reduction in fatigue.; FSS (increasing impact was rated 1–7 days 1 and 7 (averaged)): between groups effect size 2.55 (P=0.0002); Correlation with sleep stage shifts: 0.71 (P=0.0002)

a Study characteristics include number randomized per treatment arm, subpopulation if applicable, total sample size, duration of treatment, duration of observation (includes treatment period unless otherwise specified), and risk of bias (ROB).

Abbreviations: CBT=Cognitive Behavioral Therapy; CFS=Chronic Fatigue Syndrome; CGIS=Clinical Global Impressions Scale; CI=Confidence Interval; CPAP=Continuous Positive Airway Pressure; f=Cohen’s f value (0 .10=small; 0.25=medium; 0.40=large effect size); FSS=Fatigue Severity Scale; GSRH=General Self-Reported Health; IBS=Irritable Bowel Syndrome; MBB=Mind-Body Bridging; MFI=Multidimensional Fatigue Inventory; MPQ=McGill Pain Questionnaire; NR=Not Reported; NS=Not Significant; P=P-value; PA=Physician’s Assistant; PCS=Physical Component Summary; PROMIS=Patient-Reported Outcomes Measures Information System; ROB=Risk of Bias; QoL=Quality of Life; ROB=Risk of Bias; SED=Sleep Education; SF-36=36-item Short Form Survey (SF-36P=physical component); TAU=Treatment as Usual; Tx=Treatment; VAS=Visual Analog Scale; VSF-36 (also VF-36)=Veterans 36-Item Short Form Survey

Table 10 Results for cognitive, mental health, PTSD symptoms, and global outcomes in intervention trials for Gulf War Illness

Intervention and study characteristics | Cognitive symptoms | Mental health overall | Depression | Global outcomes (Function, QoL) | PTSD symptoms
Medications
Doxycycline^1^ (n=245) vs placebo (n=246); Subpopulation: positive mycoplasma DNA test; N=491; Tx duration: 12 months; Observation: 18 months; ROB: Low | CFQ:; N analyzed: 207 vs 214 Least-square mean difference at 12 months, Tx minus C (95% CI): −1.2 (−3.7 to 1.4), P > 0.2 | Veterans SF-36 MCS: N analyzed: 199 vs 212 Least-square mean difference at 12 months, Tx minus C (95% CI): 0.0 (−1.8 to 1.8), P > 0.2 | NR | NR | NR
Mifepristone^2^ (n=18 in each phase 1 and 2) vs placebo (n=18 in phase 1, n=15 in phase 2), 6-week crossover Tx phases separated by 1-month washout; Phase 1 N=36; Phase 2 N=33; Tx duration: 6 weeks; Observation: 4 months; ROB: Some concerns | MATRICS Consensus Cognitive Battery (Overall mean change, ΔT minus ΔC (SD)): 0.10 (6.83), P=0.937; Working memory: 0.16 (8.26), P=0.914; Verbal learning: 5.23 (10.29), P=0.008; Visual learning: −0.94 (11.12), P=0.643; Overall: 0.10 (6.83), P=0.937; CFQ Overall mean change, ΔT minus ΔC (SD): 1.06 (15.46), P=0.700 | SF-36 MCS overall mean change, ΔT minus ΔC (SD):; −1.89 (12.49), P=0.423 | BDI overall mean change, ΔT minus ΔC (SD): 0.88 (9.22), P=0.595 | NR | PCL overall mean change, ΔT minus ΔC (SD): −3.38 (12.26), P=0.130
Naltrexone^3^ vs placebo (n’s=NR), crossover phases separated by 1-month washout.; Total N=40; Tx duration: 3 months; Observation: 7 months; ROB: High | Attention-related problems (CPT; mean change in hit response time): −7.33 ± 6.92 (95% CI: −21.49 to 6.72) vs −0.88 ± 7.98 (95% CI: −15.3 to 17.09) (P=0.43) | NR | NR | NR | NR
Rifaximin^4^ (n=27) vs placebo (n=23); Subpopulation: IBS (Rome III); N=50; Tx duration: 2 weeks; Observation: 2 weeks; ROB: Some concerns | NR | NR | NR | IBS-QoL, change mean (SE), Tx vs C:; Dysphoria: 6.62 (4.31) vs 11.30 (4.82), P=0.50; Interference with activity: 8.40 (5.10) vs 4.95 (4.76), P=0.52; Body image: 8.09 (4.14) vs 12.02 (4.93), P=0.83; Health worry: 3.92 (4.29) vs 10.26 (5.35), P=0.39; Food avoidance: 7.35 (6.35) vs 6.41 (5.27), P=0.26; Social reaction: 4.78 (4.14) vs 0.48, P=0.28; Sexual score: 3.68 (6.59) vs −3.85 (4.98), P=0.77; Relationships: 2.19 (3.54) vs −3.65, P=0.17; Overall (all items): 6.23 (4.00) vs 6.50 (3.82), P=0.86 | NR
Nutritional Supplements
Carnosine^5^ (n=12 finished study) vs placebo (n=13 finished study); N=34; Tx duration: 12 weeks; Observation: 14 weeks; ROB: High | Cognition (WAIS-R digit symbol substitution test): Significant improvement within carnosine group between week 0 - 12 (P=0.046) vs no change with placebo.; Trail Making Tests: No difference between groups | NR | NR | NR | NR
CoQ10 ^6^; Q100 (n=11) vs Q300 (n=12) vs placebo (n=23); N=46; Tx duration: 3.5 +/− 0.5 months; Observation: 3.5 +/− 0.5 months; ROB: High | Backward digit span, change from baseline, mean diff (SE): Q100 (n=11) vs placebo (n=20): −0.13 (0.71); 95% CI −1.57 to 1.32, P=0.86 Q300 (n=11) vs placebo (n=20): −0.22 (0.85); 95% CI −1.96 to 1.53, P=0.80 | NR | NR | NR | NR
Psychological, exercise, or multi-component interventions
CBT+Exercise^7^ (n=266) vs CBT (n=286) vs Exercise (n=265) vs TAU (n=270); Total N=1092; Tx duration: 12 weeks; Observation: 12 months; ROB: Some concerns | CFQ (positive changes indicate improvement) Mean changes from baseline, adjusted for study design, pending disability claims, and baseline values:; TAU: −0.67 (P=NS); CBT + Exercise: 3.38 (P < 0.01); Exercise: 2.98 (P < 0.01); CBT: 2.66 (P < 0.025) | VSF-36 MCS score: Mean change from baseline, adjusted for study design, pending disability claims, and baseline values ((positive changes indicate improvement):; TAU: −1.03 (P=NS); CBT + Exercise: 2.30 (P < 0.01); Exercise: 2.33 (P < 0.01); CBT: 0.97 (P < 0.025); VSF-36 Mental Health Index:; TAU: −1.60 (P=NS); CBT + Exercise: 2.95 (P < 0.01); Exercise: 3.27 (P < 0.01); CBT: 1.37 (P=NS) | NR | NR | NR
Detox regimen^8^ (n=22) vs waitlist (n=10); N=32; Tx duration: 4–6 weeks; Observation: 3 months; ROB: Some concerns | NR | VF-36 MCS (Positive changes indicate improvement): Difference in score (95% CI) between Waitlist and Tx at Week 6, adjusted for baseline: 9.5 (3.1 to 15.8); P=0.003; Role-emotional: 15.2 (−4.9 to 35.2) P=0.1; Mental health: 17.7 (5.3 to 30.0) P=0.005 | NR | Subscales of VF-36 mental:; Social functioning: 15.9 (−3.9 to 35.7) P=0.1 | NR
Mindfulness-based stress reduction^9^ (n=26) vs TAU (n=29); N=55; Tx duration: 8 weeks; Observation: 6 months; ROB: Some concerns | CFQ: intervention group reported more cognitive failures post-treatment: f=0.44; P=.002; 6 months: f=0.40; P < .001 | NR | PHQ-9: reduction in depressive symptoms greater for treatment group, at both post-treatment and 6 months:; Post-treatment: f=0.22; P=.050; 6 months: f=0.27; P=.031 | NR | PSS-I: reduction in PTSD symptoms greater for treatment group post-treatment, but not 6 months:; Post-treatment: f=0.40; P=0.004; 6 months: f=0.27; P=0.08; Veterans with PTSD at baseline (N=45) randomized to treatment group had significantly greater reductions in PTSD symptoms vs TAU post-treatment, but not 6 months:; Post: f=0.44; P=.005; 6 months: f=0.31; P=.082
Sleep focused mind-body bridging^10^ (n=33) vs sleep education (n=27); Subpopulation: sleep disturbance; N=60; Tx duration: 3 sessions over 3 weeks; Observation: 3 months; ROB: Some concerns | Cognitive failure (CFQ total score), unadjusted means (95% CI):; Pre: (51.7 to 62.5) vs 55.9 (46.2 to 65.6); Post: 49.9 (42.4 to 57.3) vs 46.0 (35.1 to 57.0); At 3 months: 50.6 (40.6 to 60.6) vs 46.7 (35.6 to 57.9); “no reliable treatment effects” | BSI (global severity index), unadjusted means (95% CI):; Pre: 24.8 (20.5 to 29.0) vs 25.4 (20.3 to 30.4); Post: 23.0 (18.2 to 27.9) vs 20.4 (14.1 to 26.6); At 3 months: 20.2 (15.6 to 24.9) vs 23.5 (16.1 to 30.9); “no reliable treatment effects” | Depression (CES-D total score), unadjusted means (95% CI):; Pre: 27.4 (25.2 to 29.5) vs 26.2 (23.2 to 29.2); Post: 25.4 (22.5 to 28.3) vs 24.9 (21.5 to 28.2); Observation: 22.8 (20.5 to 25.2) vs 27.0 (22.6 to 31.4); No between-groups difference for post randomization treatment (p=.17) or treatment by period interaction (p=.080).; Observation: significantly greater improvement with MBB in customized between-groups contrasts (adjusted mean): effect size=0.71 (P=.038) | No treatment effects; QoL (SF-36 total score), unadjusted means (95% CI):; Pre: 43.8 (38.6 to 48.9) vs 43.0 (35.8 to 50.1); Post: 48.4 (42.6 to 54.1) vs 46.4 (39.6 to 53.2); Observation: 48.2 (42.0 to 54.4) vs 44.2 (35.82 to 52.5); QoL (SF-36 pain), unadjusted means (95% CI):; Pre: 38.9 (30.8 to 47.0) vs 37.9 (29.5 to 46.2); Post: 46.6 (37.9 to 55.4) vs 39.1 (30.0 to 48.3); Observation: 45.0 (36.6.0 to 53.5) vs 39.5 (28.6 to 50.4) | PCL-M total score adjusted mean improvement:; MBB; Post-Tx: 3.30 (p=.027); 3m observation: 5.45 (p=.001); SED; Post-Tx: not significant (P=0.72); 3m observation: not significant (P=0.19).; The 2 groups differed for the post randomization treatment effect (p=.038).; MBB was more effective than SED in decreasing PCL-M scores.
Other interventions
CPAP active^12^ (n=9) vs sham CPAP (n=9); Subpopulation: sleep-disordered breathing; N=18; Tx duration: 3 weeks; Observation: 3 weeks; ROB: Low | Treatment group experienced 33% improvement in cognitive function.; Cognitive VAS (0–10 daily): between groups effect size 1.67 (P=0.004); Cognition correlation with sleep stage shifts: 0.64 (P=0.006) | Treatment group experienced 16% improvement in mental health.; SF-36 mental: between groups effect size 1.29 (P=0.03); Correlation with sleep stage shifts: −0.58 (P=0.015) | NR | NR | NR

a Study characteristics include number randomized per treatment arm, subpopulation if applicable, total sample size, duration of treatment, duration of observation (includes treatment period unless otherwise specified), and risk of bias (ROB).

Abbreviations: BDI=Beck Depression Inventory; BSI=Brief Symptom Inventory; CBT=Cognitive Behavioral Therapy; CES-D=Center for Epidemiological Studies-Depression Scale; CFQ=Cognitive Failures Questionnaire; CI=Confidence Interval; CPAP=Continuous Positive Airway Pressure; CPT=Connors Continuous Performance Test; f=Cohen’s f value (0 .10=small; 0.25=medium; 0.40=large effect size); IBS-QoL=Irritable Bowel Syndrome Quality of Life; MATRICS=Measurement and Treatment Research to Improve Cognition in Schizophrenia; MBB=Mind-Body Bridging; MCS=Mental Component Score; NR=Not Reported; P=P-Value; PCL=PTSD Checklist; PHQ-9=Patient Health Questionnaire 9-item; PSS-I=PTSD Symptom Score interview; PTSD=Post-Traumatic Stress Disorder; QoL=Quality of Life; ROB=Risk of Bias; SE=Standard Error; SED=Sleep Education; SF-36=36-Item Short Form Survey; TAU=Treatment as Usual; Tx=Treatment; VAS=Visual Analog Scale; VSF-36 (also VF-36)=Veterans 36-Item Short Form; WAIS-R-Wechsler Adult Intelligence Scale-Revised

Table 11 Results for gastrointestinal symptoms and sleep outcomes in intervention trials for Gulf War Illness

Intervention and study characteristics^a^ | Gastrointestinal Symptoms | Sleep Outcomes
Medications
Rifaximin^4^ (n=27) vs placebo (n=23); Subpopulation: IBS (Rome III); N=50; Tx duration: 2 weeks; Observation: 2 weeks; ROB: Some concerns | IBS symptoms (BDQ) - difference (T minus C, change from baseline), (95% CI), P value:; Stool frequency: 0.2 (−0.2, 0.6), P=0.38; Stool consistency: 0.3 (− 0.2, 0.9), P=0.25; Urgency: 0.0 (−0.2, 0.3), P=0.88; Abdominal pain: 0.1 (− 0.4, 0.7), P=0.71; Bloating: 0.1 (−0.5, 0.6), P=0.86; Global improvement: 0.0 (−0.6, 0.6), p > 0.99 | NR
Nutritional Supplements
Carnosine^5^ (n=12 finished study) vs placebo (n=15 finished study); N=27; Subpopulation: IBS (Rome II); Tx duration: 12 weeks; Observation: 14 weeks; ROB: High | Within groups: Tx group had reduced stool frequency and watery consistency from weeks 0 to 12 (P=0.019) vs no changes in placebo group. | NR
Psychological, exercise, or multi-component interventions
Sleep focused mind-body bridging^10^ (n=33) vs sleep education (n=27); Subpopulation: sleep disturbance; N=60; Tx duration: 3 sessions over 3 weeks; Observation: 3 months; ROB: Some concerns | NR | Adjusted mean SPI-II scores were similar between SED and MBB for the overall treatment effect (p=.32).; Sleep problems in MBB declined to a greater extent than did those in SED (p=.046, effect size=.70).; The adjusted mean improvements, MBB vs SED:; Post-treatment: 16.88 vs 14.69; At 3 months: 20.70 vs 12.63; All were sig. different from baselines (p < .001).; PA-assessed changes in sleep, SED vs MBB (P for between group difference):; Improved: 7 (26.9%) vs 17 (58.6%), P <0.05
Other interventions
CPAP active^12^ (n=9) vs sham CPAP (n=9); Subpopulation: sleep-disordered breathing; N=18; Tx duration: 3 weeks; Observation: 3 weeks; ROB: Low | NR | Quality of sleep (PSQI; rated 0–21 on days 1 and 7 (averaged)): Treatment group experienced 41% improvement. Slightly poorer in sham group (assessed by sleep parameters), but no significant between-group differences.; PSQI: between groups effect size 2.67 (P=0.0003); Correlation with sleep stage shifts: 0.59 (P=0.016)

a Study characteristics include number randomized per treatment arm, subpopulation if applicable, total sample size, duration of treatment, duration of observation (includes treatment period unless otherwise specified), and risk of bias (ROB).

Abbreviations: BDQ=Bowel Disease Questionnaire; CBT=Cognitive Behavioral Therapy; CI=Confidence Interval; CPAP=Continuous Positive Airway Pressure; IBS=Irritable Bowel Syndrome; MBB=Mind-Body Bridging; NR=Not Reported; P=P-value; PSQI=Pittsburgh Sleep Quality Index; ROB=Risk of Bias; SED=Sleep Education; SPI-II=Stroke Prognosis Instrument 2.

Table 12 Adverse events in published intervention studies for Gulf War Illness

Treatment (Sample size) | N participants | Adverse events
Acupuncture ^11^ | 104 | 1 in biweekly treatment group reported pain on needling;; 1 in weekly treatment group reported suicidal thoughts
Carnosine ^5^ | 34 | 1 asymptomatic elevation of alanine-serine transaminase plus interval increase in CRP, considered not related to study drug.
CBT, Exercise, CBT + Exercise ^7^ | 1092 | 112 serious AEs, mostly “hospitalizations unrelated to the study”:; 23 CBT + exercise; 27 exercise; 30 CBT; 32 TAU; 3 AEs possibly related:; 2 TAU (psychosis and angina); 1 back surgery (exercise arm)
CoQ10^6^ | 46 | 2 neurological events, both placebo.
CPAP^12^ | 18 | ---
Detox regimen^8^ | 32 | Discomfort and nausea from sauna; flushing and itching from niacin; pre-syncope; IBS; hypokalemia
Doxycycline^1^ | 491 | Significantly more nausea and photosensitivity with doxycycline vs placebo.; No significant difference in myalgia.
Mifepristone^2^ | 36 | 1 on mifepristone developed a rash that resolved after ceasing drug
Mindfulness-based stress reduction^9^ | 55 | ---
Naltrexone^3^ | 40 | 1 w/d due to dizziness with naltrexone.
Rifaximin^4^ | 50 | No differences
Sleep focused mind-body bridging vs sleep education^10^ | 60 | ---

Abbreviations: CBT=cognitive behavioral therapy; CPAP=continuous positive airway pressure; CoQ10= coenzyme Q10; TAU=treatment as usual.

Table 13 Details of ongoing and unpublished controlled trials of interventions/management strategies for Gulf War Illness

Intervention; Registration; Study Design; Sponsors; Setting | Study Title | Status; completion date | Purpose of study | Participants; Intervention(s)/Comparator | GWI case definition | Outcome(s) and timing
Behavioral
CBT ^26^; NCT02782780; RCT; VA ORD; San Francisco VAMC | Cognitive Behavioral Therapy for Insomnia for Gulf War Illness | Recruiting as of July 2019; E: May 30, 2020 | “examine the efficacy of telephone-delivered CBTi for alleviating sleep and non-sleep GWI symptoms in a 2-arm randomized controlled trial” | 80 deployed GW Veterans meeting Gulf War Registry criteria, Kansas definition, and Insomnia severity index score of 14 or greater; 8 weekly, individual sessions of Cognitive Behavioral Therapy for Insomnia (CBTi) vs usual care/waitlist | Kansas | 1°^:^ Insomnia severity (ISI); sleep quality (PSQI); GWI symptoms (modified Kansas questionnaire); sleep latency, minutes of wake after sleep onset, sleep efficiency (self-report sleep diary); 2°: fatigue (FSS); pain (BPI); cognitive function (MASQ); anxiety and depressive symptoms (HADS); Time frame: baseline, 8 weeks, and 6-month follow-up
Cognitive rehabilitation ^27^; NCT02161133; RCT; VA ORD; VAMCs Bedford, MA; East Orange, NJ; Canandaigua, NY | Cognitive Rehabilitation for Gulf War Illness | Completed Sept 2019. No results; A: September 1, 2019 | “to determine whether Problem-Solving Therapy, a patient centered cognitive rehabilitation therapy, can reduce disability by compensating for problem-solving deficits” | 268 GW Veterans with GWI, scores at least half a standard deviation worse than the mean on the WHODAS 2.0; Cognitive rehab (problem-solving therapy) vs Health education | Kansas | 1°: Disability (WHODAS 2.0); 2°: problem-solving inventory (self-report), problem-solving ability (Neuropsychological Battery includes: Halstead Category Test, Russell Revised Version; CPT-3, Stroop Color and Word Test, executive functioning (TMT parts A and B), FIT, fatigue (FSS), and pain (PDI and MPI composite score); Time frame: 12 weeks
MBSR ^28^; NCT03058952; RCT; VA ORD; VAPSHCS, Seattle, WA | Evaluation of a Mindfulness-Based Intervention for Gulf War Illness | Recruiting as of July 2017; E: April 30, 2021 | “to evaluate outcomes of… Mindfulness-Based Stress Reduction and an adapted version of the Chronic Disease Self-Management Program (CDSMP)…for Veterans with Chronic Multisymptom Illness (CMI).” | 308 Veterans with CMI (50% will be GWV^*^); MBSR vs adapted CDSMP | N/A (used CMI as criteria) | 1°: Pain (SF-MPQ-2); Fatigue (MFI); concentration and memory (CFQ); satisfaction with intervention (CSQ-8); 2°: Depression (PHQ-9); PTSD (PCL-C); SF-36; alcohol use disorder (NIH PROMIS Alcohol Use and Negative Consequences, short form)
Central Nervous System (CNS) Stimulation
rTMS ^23^; NCT01608321; RCT; VA ORD; VA Palo Alto Health Care System | rTMS for the Treatment of Chronic Pain in GW1 Veterans (rTMS) | Terminated (Did not meet recruitment goals as of June 2015) | “to engage in a clinical trial of rTMS in chronic pain that occurs in the context of multiple medical symptoms …in GWI diagnosed patients [with] symptoms of chronic pain in the musculoskeletal category and at least two additional symptoms.” | 206 (initially estimated) Chronic pain >= 4 on the pain severity scale of the BPI-SF Active vs sham rTMS, 20 sessions | Kansas | 1°: Change in pain (BPI-SF); Time Frame: Baseline and 3–4 weeks
rTMS ^31^; NCT03030794; RCT; Veterans Medical Research Foundation, in collaboration with DoD; Naval Medical Center and Veterans Affairs Hospital, San Diego, CA | Alleviating Headache and Pain in GWI With Neuronavigation Guided rTMS | recruiting as of Aug 2018; E: December 2018 | “assess the effect of repetitive transcranial magnetic stimulation (rTMS) on Gulf War illness related headaches and pain” | 90 pts meeting CDC and Kansas criteria with Migraines and muscle pain and joint pain; Repetitive transcranial magnetic stimulation (rTMS), 11 visits over 2 months vs Sham rTMS at same intervals | CDC and Kansas | 1°: Self-reported headache and pain (daily log); HA pain severity (HIT-6); pain level; opioid medication assessment; headache, muscle, and joint pain (VAS); 2°: Neurobehavioral symptoms (NSI); Pain (SF-MPQ); widespread pain (New Clinical Fibromyalgia Diagnostic Criteria); FIQR; HVLT; TMT A&B; executive function; depression (HAM-D); SF-36; sleep quality (PSQI); insomnia fatigue scale; Time Frame: 2 months for each subject (11 visits)
rTMS ^32^; NCT04046536; RCT; VA ORD; VA San Diego, Palo Alto, and Atlanta | rTMS in Alleviating Pain and Co-Morbid Symptoms in Gulf War Veterans Illness (GWVI) | Recruiting as of Nov 2019 E: September 30, 2024 | Assess “effectiveness of using repetitive transcranial magnetic stimulation (rTMS) in relieving pain and other co-morbid symptoms of Gulf War Illness” | 80 GW Veterans meeting CDC and Kansas, with migraines, muscle and joint pain, and depression; 4 arms:; 1. rTMS at the LDLPFC; 2. rTMS at the LMC vs; 3. Sham rTMS at the LDLPFC; 4. Sham rTMS at the LMC | CDC and Kansas | 1°: Self-reported headache and pain by daily log; SF-MPQ; HIT-6; HAM-D; SF-36; BPI-SF; pain (New Clinical Fibromyalgia Diagnostic Criteria); FIQR; sleep quality (PSQI); insomnia severity index; Flinders Fatigue Scale; 2°: PTSD symptoms (CAPS-5); opioid-based pain medication usage; supraspinal resting state functional connectivity (MRI); Time Frame: Baseline, 1-week, 1-month, 2-month, and 3-month
rTMS ^33^; NCT04182659; RCT; Veterans Medical Research Foundation & DoD; VA Palo Alto, San Diego, Atlanta | Long Term Efficacy of Neuronavigation Guided rTMS in Alleviating Gulf War Illness Related Headaches and Pain Symptoms | Recruiting as of Dec 2019; E: Sept 2022 | Assess “the effectiveness of repetitive transcranial magnetic stimulation (rTMS), non-invasive treatment option, in alleviating headaches, muscle, and joint pain symptoms of GWI.” | 150 GW Veterans with migraines, under age 65, who served at least 30 days in the conflict; Transcranial Magnetic Stimulation (rTMS) vs sham rTMS at the left motor cortex (LMC) | CDC & Kansas | 1°: pain (SF-MPQ; BPI-SF), headaches (Self-report journal; HIT-6), QoL (SF-36); fibromyalgia (New Clinical Fibromyalgia Diagnostic Criteria - Part 1; Revised Fibromyalgia Impact Questionnaire); neurobehavioral (NSI); sleep (PSQI; Insomnia Severity Index); fatigue (Flinders Fatigue Scale).; 2°: PTSD (CAPS-5); opioid-based pain medication usage; supraspinal resting state functional connectivity
(HD) tDCS ^30^; NCT03542383; RCT; The University of Texas at Dallas; Callier Center for Communication Disorders | Treatment of Memory Disorders in Gulf War Illness with High Definition Transcranial Direct Cortical Stimulation | Recruiting as of May 2018; E: Sept 29, 2019 | “determine if delivery of [High Definition transcranial Direct Current Stimulation] HD tDCS over the [PreSupplementary Motor Area] preSMA will improve performance in GWI veterans with a verbal retrieval deficit” | 120 deployed GW Veterans; HD tDCS: 10 20-minute sessions of 1 mA anodal High Definition Transcranial Direct Current Stimulation to the preSMA region over a 2-week period vs sham HD tDCS at same duration | Not specified | 1°^:^ Verbal fluency (COWAT; timing note: also applied at initial phone screen), and Verbal learning and memory (CVLT); 2°: Semantic memory (SORT); Semantic Selection Task; Time Frame: Baseline, after Tx (2 weeks), and 3- and 6-months follow-up
tDCS ^34^; NCT03547869; RCT; The University of Texas at Dallas; University of Texas Southwestern Medical Center | Transcranial Direct Current Stimulation for Pain Treatment in Gulf War Illness. | Recruiting as of July 2019; E: March 12, 2021 | “investigate long-term modulation of pain pathways leading to a suppression of pain symptoms in Gulf War Illness patients by applying transcranial direct current stimulation” | 120 GW Veterans; tDCS vs sham tDCS, 10 sessions | Not specified | 1°^:^ Pain (VAS); 2°: Brain activity (EEG); Time frame: baseline, immediately after tDCS, and 1, 4, 12, 24 weeks after the last tDCS session
VNS ^35^; NCT02791893; RCT; Benjamin Natelson VA East Orange, NJ; Icahn School of Medicine at Mount Sinai | Vagus Nerve Stimulation: Treatment for Gulf Veterans with Gulf War Illness | Recruiting as of Nov 2019; E: March 2020 | “Besides their pain, the researchers will also assess the effect of vagus nerve stimulation (VNS) in alleviating migraine headache” | 40 GWV with GWI, widespread pain, has migraine headaches; VNS hand-held device (20 weeks total, 120 second period 3x/day) vs placebo (inactive device at same frequency/duration) | Kansas | 1°^:^ Widespread pain (VAS);; 2°: Overall improvement (patient global improvement of change), SF-36, number of migraine headache days; Time frame: baseline, 10 and 20 weeks
Complementary and integrative health
Acupressure ^36^; NCT02075489; NRCT; The Cleveland Clinic | Acupressure for Pain Management and Fatigue Relief in Gulf War Veterans | Completed Oct 2017. No results; A: October 2017 | “determine the effectiveness of acupressure treatment in symptomatic veterans in fatigue relief and pain management for Gulf War Illness (GWI)” | 7 GW Veterans with GWI, severity and interference scores of 5+ by BPI, score of 3+ by Piper Fatigue Scale; Acupressure treatment (40 minutes/day, 2days/week for 6 weeks) vs Reiki (40 mins/day, 2 days/week for 6 weeks) | Not specified | 1°: Fatigue (revised PFS); 2°: changes in corticomuscular coherence (EEG and EMG surface signals), SF-36; Timing: baseline and 6 weeks
Meditation + acupuncture ^37^; NCT02180243; RCT; VA ORD; VAMC, Washington, DC | CAM in Veterans with Gulf War Illnesses | Recruiting as of Nov 2019; E: October 1, 2021 | “to explore the effectiveness Gulf War Health Education (GWHE) and iRest Yoga Nidra (meditation)/ auricular (ear) acupuncture for Veterans with Gulf War Veterans’ Illnesses (GWVI)” | 172 GW Veterans with GWI (ie fatigue, pain, cognitive impairment); iRest Yoga Nidra and auricular acupuncture vs Gulf War Health education | Not specified | 1°^:^ Sleep quality (objective and self-report sleep measures will be taken); Time frame: 1 year
Tai Chi ^38^; NCT02661997; RCT; VA ORD; VAMC Boston | Novel Interventions for GWVI | Recruiting as of Aug 2, 2019; E: March 31, 2021 | “examine the beneficial effects of two novel treatments for Gulf War Veteran’s Illness (Tai Chi and Wellness intervention) and to establish the efficacy of these mind-body approaches to symptom reduction” | 120 GW veterans with joint pain or stiffness over 6 months and meeting CDC CMI criteria; Tai Chi: 60 minutes, twice a week for 12 weeks + 30min/day home practice vs Wellness Intervention: same dose/duration + VA Whole Health video and brief mindfulness practice | CDC | 1°^:^ Change in pain (BPI-SF); 2°: Fatigue (MFI-20); PROMIS Global Health Scale; 50-foot walk test; Short Physical Performance Battery; executive functioning (TMT); verbal learning (HVLT-R) Other outcomes: various; Time frame: baseline and 12 weeks
Yoga ^39^; NCT02378025; RCT; Palo Alto Veterans Institute for Research, DoD VAMC, Palo Alto | Treating Chronic Pain in Gulf War Illness | Completed; A: March 2018 Results shown in Table 14 | “The purpose of this study is to determine whether yoga is effective for the treatment of chronic pain in Gulf War Illness” | 75 Veterans (served 1990–91 regardless of deployment) with chronic pain; Yoga (10 weeks) vs CBT (10 weeks) | CDC | 1°^:^ Pain (BPI-SF); Time frame: Weeks 0, 2, 4, 8, 10, 18, 26, and 34; 2°: SF-36, Fatigue (6-minute walk test), Changes in medication.; Time frame: Weeks 0, 10, and 34
Diet
Low-FODMAP diet ^25^ ^,^ ^40^; NCT02881944; RCT; Ashok Tuteja VAMC Salt Lake City, UT | Effect of Diet on Gulf War Illness | Completed E: September 2018 Results shown in Table 14 | “compare a low FODMAP diet to a high FODMAP diet for effect on Veterans with IBS and symptoms of Gulf War Illness” | 68 GW Veterans with IBS and 2 or more of the non-intestinal symptom groups (chronic-once a week or more often-fatigue, insomnia, joint pains, general stiffness, and headache, neurological and mood, respirator and skin symptoms) for > 6 months; Low-FODMAP diet vs high-FODMAP (typical healthy) diet for 3 weeks | Not specified | 1°^:^ Bowel symptom score (self-reported); 2°: IBS-QoL score (self-reported); Time frame: baseline and 3 weeks
Low-glutamate diet ^41^ ^,^ ^42^; NCT03342482; Crossover RCT; American University, Washington, DC | Glutamate Neuro-Excitotoxicity in GWI | Recruiting as of July 4, 2019; E: August 31, 2020 | “test the effectiveness of a low-glutamate diet in GWI patients, as a way to mediate symptom occurrence by reducing excess glutamatergic neurotransmission” | 40 Veterans deployed during GW with GWI; Phase 1: Low-glutamate diet vs waitlist (1 month); Phase 2: MSG challenge (3 consecutive days) vs placebo (2 weeks: one 3-day challenge per week, then crossover) | Kansas and CDC | 1°: Change in Brain Glutamate Levels ( MRS) at baseline and 1 month; 2°: Symptom change, and Cognitive function (computerized battery); Other: Change in brain excitation (EEG); Timing (2° and other): baseline, 1 month, and weeks 5 & 6
Exercise
Exercise training ^43^; NCT01350492; RCT; VA ORD; VAMC Madison, WI | Impact of Exercise Training on Pain and Brain Function in Gulf War Veterans | Completed. No results posted as of April 5, 2019;A: December 31, 2018 | “test the influence of weight training on physical symptoms, physical activity and brain structure and function inGulf War Veterans with chronic widespread muscle pain” | 77 Gulf War Veterans with chronic musculoskeletal pain; Resistance exercise training (16 weeks) vs Waitlist | Not specified | 1°^:^ Symptoms (self-report and EHR); 2°: Physical activity (accelerometer and self-report), brain structure and function (6 MRI scans over course of study); Time frame: baseline, during exercise phase, and 6- and 12-months post-exercise
Medications
D-cycloserine ^44^; NCT02983734; RCT; Boston University Charles River Campus | D-cycloserine: A Novel Treatment for Gulf War Illness (GWDCS) | Recruiting Jan 2019; September 2019 | “investigate the efficacy of d-cycloserine (DCS) treatment for Gulf War Illness (GWI)” | 56 GW Veterans meets GWI criteria with cognitive symptom domain; D-cycloserine 100mg/day for 4 weeks vs placebo | Not specified | 1°^:^ Neuropsychological Test Battery; 2°: Symptom Questionnaires; Time frame: 8 weeks per subject
Etanercept+ mifepristone ^45^; NCT04254627; Phase I; Nova Southeastern University, RTI International, Rochester General Hospital | Tumor Necrosis Factor (TNF) and Glucocorticoid Antagonist for Gulf War Illness (GWI)-Associated Multi-symptom Disease Homeostasis Reset | Not yet recruiting as of Mar 2020; E: July 2021 | “assess the safety and mechanistic efficacy of a sequential etanercept-mifepristone intervention for Gulf War Illness” | 20 males, 45–70 yrs, with trauma, meeting CDC & Kansas criteria for GWI; Etanercept 50 mg weekly injection for 12 weeks, followed by 1 week of mifepristone at either 300 or 600 mg/day | CDC & Kansas | 1°^:^ Safety
Duloxetine vs pregabalin ^24^; NCT01846182; RCT; VA ORD; Central Texas Health Care System and Central Texas VAMC (Waco, TX) | RCT of Duloxetine & Pregabalin for the treatment of Gulf War Illness in Veterans | Terminated Jan 2020 | “Test the efficacy of Duloxetine and Pregabalin for treating Gulf War Veterans who suffer from GWI” | 162 English-speaking GW Veterans with pain and GWI; 3 arms: 60mg duloxetine (taken daily in AM) vs 300mg pregabalin (taken daily in PM) vs placebo (taken daily AM & PM), for 20 weeks | Kansas | 1° Pain (10-point VAS; PCS of SF-36); 2°: Side effects (checklist); Time frame: every 2 weeks up to 34 weeks
Intranasal insulin ^46^; NCT01802944; RCT; Bronx Veterans Medical Research Foundation, Inc.; Bronx and Boston VAMCs | Intranasal Insulin: A Novel Treatment for Gulf War Multisymptom Illness | Unknown as of Oct 2017; E: December 2017 | Examine whether intranasal insulin improves cognitive function and other CMI symptoms in GW Veterans with CMI | 114 GW veterans with CMI, must include cognitive domain (Kansas); 2 dose groups: 10 IU BID and 20 IU BID intranasal insulin vs placebo | Kansas | 1°^:^ Memory functioning (CVLT), and attention functioning (Stroop Color-Word Interference Task). Secondary: Physical health (PCS of the SF-12V), mood (POMS vigor scale); Time frame: baseline, 8 weeks, and 1-month follow-up
Prednisone ^47^; NCT02506192; RCT; Minneapolis VAMC; DoD is a collaborator | Gulf War Illness Inflammation Reduction Trial | Recruiting as of Aug 2019; E: October 2020 | “determine if treatment with an anti-inflammatory drug (delayed-release prednisone) improves the health-related quality of life (HRQoL) of veterans with Gulf War Illness (GWI)” | 100 GW vets deployed to Kuwaiti Theater of Operation, and scores moderate-severe on at least 3 out of 6 domains from the Kansas GWI case definition; Delayed-Release Prednisone oral tablets (2x5mg) daily for 8 weeks vs placebo | Kansas | 1°^:^ SF-36 PCS.; Time frame: 0, 8, and 16 weeks; 2°: Pain (MPQ); Fatigue (MFI); Cognitive symptoms (CFQ); SF-36 MCS; blood biomarkers (MAP and CBC)
Pregnenolone ^48^; NCT01956279; RCT; VA ORD; VA Durham, NC | Complementary Neurosteroid Intervention in Gulf War Illnesses (GWVI) | Completed Oct 2018; A: October 10, 2018 | “investigate the use of adjunctive pregnenolone for” fatigue, musculoskeletal pain, and cognitive decline | 170 GW deployed Veterans; Pregnenolone: 250 mg BID for 28 days after titration phase (titration starting at 50mg BID increasing by 100mg every 2 wks) vs placebo | modified CDC | 1°: SF-36 Physical component; 2°: Pain (BPI); executive functioning (Tower of London from BAC-A); Fatigue (MFSI); psychiatric symptoms (SCL-90R); Time frame: baseline (2 weeks), 6 and10 weeks
Rituximab ^49^; GW160123; RCT; DoD; Nova Southeastern University | The Use of BCell Depletion Therapy (BCDT) in Gulf War Illness: A Phase 1/2 Study | NR; NR | “to evaluate the efficacy and safety of rituximab, validate the presence of central nervous system autoantibodies and decrease their presence with B-cell depleting therapy such as rituximab, and reset underlying mechanisms of disease to improve symptoms and reset homeostasis. | NR; Rituximab (2 infusions with 2 weeks’ interval (500 mg/m2, max. 1000 mg)) vs Placebo: Saline infusion | Not specified | 1°: SF-36 (PCS and vitality), and levels of autoantibodies against neuronal glial proteins; Time frame: 6 weeks, and 3, 6, and 9 months after initial administration of rituximab or placebo
Nutritional supplements
Botanical Microglia Modulators ^51^; NCT02909686; Crossover RCT; University of Alabama at Birmingham; CDMRP is a collaborator | Effects of Botanical Microglia Modulators in Gulf War Illness | Active as of Oct 2019; E: Sept 2020 | test if any botanical agents that “suppress microglia function in a way that is anti-inflammatory and neuroprotective…suppre ss symptoms in GWI” | 64 male GW Veterans with GWI; Botanical compounds daily values: Boswellia serrata 400–800mg, curcumin 1000–2000mg, Epimedium 1000–2000mg, fisetin 200–800mg, luteolin 200–400mg, nettle 435–1305mg, Pycnogenol 200–400mg, reishi mushroom 1600–3200mg, resveratrol 200–600mg vs placebo | Kansas | 1°^:^ GWI severity (self-report scale: 0–100 2x/day); 2°: self-reported pain, fatigue, cognitive symptoms, mood, dermatological symptoms, respiratory symptoms, and GI symptoms; Time frame: the last 2 weeks of each treatment, compared to average severity during the last 2 weeks of placebo; baseline
Concord grape juice ^52^; NCT02915237; RCT; Icahn School of Medicine at Mount Sinai in collaboration with DoD; VA East Orange, NJ | Development of a Polyphenol-rich Dietary Preparation for Treating Veterans with Gulf War Illness | Completed Mar 2019. No results posted; A: January 17, 2019 | “the goal is to test whether daily consumption of commercially available Concord grape juice is effective for treating cognitive deficits and chronic fatigue in Veterans with GWI” | 36 GW Veterans with GWI; Concord grape juice (low 4oz dose, moderate 8oz dose, and high 16oz dose) vs placebo beverage | Kansas | 1°^:^ Safety and tolerability to treatment (BSI and PHQ-15), cognitive functioning (CVLT-II), chronic fatigue (CFQ11); 2°: Auditory attention (WAIS-IV - digit span subtest), attention (CPT-3), graphomotor speed and executive functioning (TMT), intelligence level (WAIS-IV block design subtest), color and word test (Stroop test), Halstead Category Test, learning and memory (BVMT-R), auditory memory and attention (WAIS-IV); Time frame: 6 months
Mitochondrial cocktail ^53^; NCT02804828/GW140146; Controlled trial (not clear if randomized) University of California, San Diego | Mitochondrial Cocktail for Gulf War Illness | Not yet recruiting as of Dec 2018; E: Sept 2019 | “assess the benefit of a mitochondrial cocktail plus individualized correction of citric acid cycle (CAC) intermediates and amino acid (AA) abnormalities as part of a mitochondrial/ oxidative stress treatment approach in Gulf War Illness (GWI).” | Meet CDC and Kansas GWI criteria; Individualized mitochondrial cocktail & Arctic cod liver oil capsules vs placebo | CDC and Kansas | 1°^:^ Predictive GWI biomarkers (α-ketoglutarate, fumarate, malate, citrate, and isocitrate); Time Frame: baseline, 6, and 12 months
Resveratrol ^54^; NCT03665740; RCT; VISN 17 CoE, Waco, Texas | Multimodal Investigation of the Neuroprotective Effects of Resveratrol (MINER) | Recruiting as of Sept 2018; E: August 31, 2022 | Examine whether “resveratrol treatment will improve memory issues, difficulties with thinking and mood problems in Veterans with GWI” | 68 veterans deployed in GW meeting criteria Kansas and CDC criteria for GWI; 2000mg Resveratrol for 6 weeks (following titration from 500mg in 500mg increments every 6 weeks) vs identical placebo | Kansas and CDC | 1°^:^ Cognitive function (CVLT-II), mood (BDI-II), and daily functioning (WHODAS 2.0); 2°: hippocampus scans (MRI and DTI); Time frame: baseline and 26 weeks
Ubiquinol ^55^; NCT02865460; RCT; VA Office of Research and Development; VA Miami, Boston, Minneapolis, and Bronx Health Care Systems | CoQ10 in Gulf War Illness | Recruiting as of Oct 2019; E: Sept 30, 2020 | “determine if treatment with ubiquinol improves the physical function of men and women Veterans suffering from GWI” | 200 GWV who were in good health prior to 1990. currently with moderate-severe GWI; Ubiquinol: 2x200mg for 2 months; 1x200mg for 4 months vs placebo | Kansas | 1°: SF-36 every 4 wks to 28 wks; 2°: Fatigue (MFI), GWI symptoms, pain (BPI), Sleep (PSQI), anxiety (HAM-A), physical activity (FitBit), trauma (DTS), cognitive symptoms (CPT-3), recall and memory (CVLT-II), visual memory (BVMT), GWI associated blood biomarkers (CBC), depression (HAM-D), circadian rhythm (cortisol levels through saliva), thyroid status (HPT axis levels), HPG axis levels
Visbiome vs VSL#3 ^56^; NCT03078530; RCT; Ashok Tuteja; DoD VAMC Salt Lake City, UT | Probiotic (Visbiome) for Gulf War Illness | Recruiting as of Dec 2017; E: May 31, 2018 | “determine whether Visbiome will improve intestinal symptoms of IBS and non-intestinal symptoms (fatigue, joint pain, insomnia, general stiffness and headache) associated with IBS” | 60 GW Veterans with IBS and 2 or more non-intestinal symptoms > 6 months; Three arms: Visbiome vs VSL#3 vs placebo | Not specified | 1°^:^ IBS-related symptoms (BSS at 8 weeks); 2°: chronic fatigue (1–5 scale; Baseline to 4 and 8 weeks)
Other
Electrical stimulation (stochastic noise)^57,70^; Proposal: GW130093; DoD CDMRP; Rutgers, Newark, NJ | Use of a Portable Stimulator to Treat GWI | Completed; poster presented at Neuroscience Nov 2018.; Results shown in Table 14 | “We hypothesize that stimulation of the vestibular system with electrical stochastic noise via surface electrodes will produce immediate and long-term improvements in vestibular function and balance.” | 60 GW Veterans with GWI and vestibular loss; Stochastic noise electrical stimulation vs sham electrical stimulation bilaterally through ear clips for 12 weeks | Not specified | 1°^:^ Ocular torsion; sway; balance; dizziness
LED therapy ^58^; NCT01782378; Crossover RCT; VA ORD; VA San Francisco and Boston | Scalp Application of Red and Near-Infrared Light, From Light-Emitting Diodes (LED) to Improve Thinking and Memory in Veterans with Gulf War Illnesses | Active - not recruiting. Mar 2019. Results submitted; E: December 31, 2019 | “learn if an experimental [LED] treatment can help thinking ability, and memory in Veterans with Gulf War Veterans Illnesses (GWVI)” | 160 GW Veterans meeting CDC and Kansas criteria, and with neuropsychological symptoms; Real LED Treatment Series First vs Sham LED Treatment Series First. 15 sessions with helmet (real or sham) and intranasal devices | CDC and Kansas | 1°: Attention/Executive Function (Stroop Test); 2°: Additional Attention/Executive Function (WAIS-IV and D-KEF); learning and memory (CVLT-II); Mood (BDI); SF-36 physical; blood tests: mitochondrial function, inflammation, coagulation
Nasal Irrigation (Xylitol vs saline) ^59^ ^,^ ^60^; NCT01700725; RCT; University of Wisconsin, Madison | Effectiveness of nasal irrigation for chronic rhinosinusitis and fatigue in patients with Gulf War illness: protocol for a randomized controlled trial | Completed; A: May 2017 Results shown in Table 15 | “to determine whether nasal irrigation with Xylitol or saline are effective in the treatment of chronic rhinosinusitis and fatigue symptoms associated with Gulf War Illness” | 40 deployed GW Veterans with GWI and chronic rhinosinusitis (CRS); Three arms: Nasal Irrigation (NI) with saline vs NI with xylitol vs usual care | modified Kansas | 1°^:^ QoL (SNOT-20); 2°: Fatigue (MFI); HRQoL (SF-36); cost-effectiveness ratio; treatment satisfaction (7-point Likert); Other: laboratory stress- and illness-related biomarkers

* Only analyses of this subpopulation alone would be included for purposes of answering our key questions

Abbreviations: A=Actual; BAC-A=Brief Assessment Checklist for Adolescents; BID=bis in die; BPI=Brief Pain Inventory; BPI-SF=Brief Pain Inventory-Short Form; BSI=Brief Symptom Inventory; BSS=Bowel Symptom Scale; BVMT-R=Brief Visuospatial Memory Test-Revised; CAPS-5=Clinician-Administered PTSD Scale for DSM-5; CBC=Complete Blood Count; CBTi=Cognitive Behavioral Therapy for Insomnia; CDC=Centers for Disease Control and Prevention; CDMRP=Congressionally Directed Medical Research Programs; CDSMP=Chronic Disease Self-Management Program; CFQ11=Chalder Fatigue Scale; CMI=Chronic Multisymptom Illness; CoE=Center of Excellence for Research on Returning War Veterans; CoQ10=Coenzyme Q_10_; COWAT=Controlled Oral Word Association Test; CPT-3=Conner’s Continuous Performance Test - 3rd Edition; CRS=chronic rhinosinusitis; CVLT-II=California Verbal Learning Test Second Edition; DCS=d-cycloserine; D-KEF=Delis-Kaplan Executive Function System; DTI=Diffusion Tensor Imaging; DTS=Davidson Trauma Scale; E=Estimated; EHR=Electronic Health Record; EEG=Electroencephalogram; EMG=Electromyography; ERP=Event Related Potential; FIQR=Revised Fibromyalgia Impact Questionnaire; FIT=Rey 15-Item Test; FODMAP=Fermentable Oligo-, Di-, Mono-saccharides And Polyols; FSS=Fatigue Severity Scale; GI=Gastrointestinal; GW=Gulf War; GWHE=Gulf War Health Education; GWI=Gulf War Illness; GWV=Gulf War Veteran; GWVI=Gulf War Veterans Illness; HA=Headache; HADS=Hospital Anxiety and Depression Scale; HAM-A=Hamilton Anxiety Rating Scale; HAM-D=Hamilton Depression Rating Scale; HD-tDCS=High Definition transcranial Direct Current Stimulation; HIT-6=Headache Impact Test; HPG=Hypothalamic-Pituitary-Gonadal; HPT=Hypothalamic–Pituitary–Thyroid; HRQoL=Health-related Quality of Life; HVLT-R=Hopkins Verbal Learning Test – Revised; IBS=Irritable Bowel Syndrome; ISI=Insomnia Severity Index; LDLPFC=Left Dorsolateral Prefrontal Cortex; LED=Light Emitting Diode; LMC=Left Motor Cortex; MAP=Mean Arterial Pressure; MASQ=Mood and Anxiety Symptoms Questionnaire; MBSR=Mindfulness-based Stress Reduction; MCS=Mental Component Summary; MFI-20=Multidimensional Fatigue Inventory-20; MFSI=Multidimensional Fatigue Symptom Inventory; MPI=Multidimensional Pain Inventory; MPQ=McGill Pain Questionnaire; MRI=Magnetic Resonance Imaging; MRS=Magnetic Resonance Spectroscopy; MSG=Monosodium Glutamate; NI=Nasal Irrigation; NIH=National Institutes of Health; NR=Not Reported; nRCT=non-Randomized Controlled Trial; NSI=Neurobehavioral Symptom Inventory; ORD=Office of Research and Development; PCS=Physical Component Summary; PDI=Pain Disability Index; PFS=Piper Fatigue Scale; PHQ-9=Patient Health Questionnaire 9-item; PHQ-15 Patient Health Questionnaire 15-item; PI=Principal Investigator; preSMA=PreSupplementary Motor Area; PROMIS=Patient Reported Outcomes Measurement Information System; PSQI=Pittsburgh Sleep Quality Index; PTSD=Posttraumatic Stress Disorder; QoL=Quality of Life; rTMS=Repetitive Transcranial Magnetic Stimulation; SCL-90R=Symptom Checklist-90-Revised; SF-12V=Standard Form 12-Veteran Version; SF-36=36-Item Short Form Health Survey; SF-MPQ=Short-Form McGill Pain Questionnaire; SNOT-20: Sinonasal Outcome Test-20; SORT=Semantic Object Retrieval Test; tDCS=Transcranial Direct Current Stimulation; TMT=Trail Making Test; VAMC=Veterans Affairs Medical Center; VAPSHCS=Veterans Affairs Puget Sound Health Care System; VAS=Visual Analog Scale; VNS=Vagus Nerve Stimulation; VSL=Very Safe Lactobacilli; WAIS-IV=Wechsler Adult Intelligence Scale-Fourth Edition; WHODAS=World Health Organization Disability Assessment Schedule

Table 14 Details of single-arm studies of interventions/management strategies for Gulf War Illness

Intervention; Study Design; Sponsors; Setting | Study Title | Purpose of study | Participants; Intervention(s) | GWI case definition(s) | Outcome(s) and timing
Specialized Care Program ^29^; Single-arm pilot intervention Sponsors not specified: Acknowledgements included - US Army Lieutenant General Ronald R. Blanck Setting not specified | Rehabilitative care of war-related health concerns | “to present SCP data comparing longitudinal health outcomes with baseline health status among a series of Gulf War veterans with persistent symptoms” | 109 veterans; Specialized Care Program (SCP): 3-week intensive outpatient group program. Medical assessment; collaboration with providers and other GW veterans to develop “symptom-management plan - an individualized combination of regular primary medical care, exercise, self-care, and other active coping strategies” | Not specified | SF-36; Physical symptoms (PRIME-MD patient questionnaire), quality of life, physical health concern (Whitely Index), and psychosocial distress (Somatization, Depression, and Anxiety scales of the BSI) contrasted across time and demographic groups; Time frame: SCP entry, exit, and at 1 and 3 months after exit.
Nutrient formula + methylphenidate ^50^; DoD grant to K-PAX Pharmaceuticals; VA Palo Alto Health Care System, Palo Alto, CA | Treatment for Gulf War Illness (GWI) with KPAX002 (methylphenidate hydrochloride + GWI nutrient formula) in subjects meeting the Kansas case definition: A prospective, open-label trial | “tested the safety, tolerability, and efficacy of KPAX002--a combination of methylphenidate hydrochloride plus a micronutrient formula designed to support mitochondrial function—as a treatment for Gulf War Illness (GWI)” | 15 Veterans with GWI; GWI Nutrient Formula (4 tablets twice daily) and methylphenidate hydrochloride (5mg twice daily for Week 1 and 10mg twice daily for Week 2–12) | Kansas | 1°: Symptoms (GWI SAT; quant scores 0–87); 2°: symptomatology and disability potential (CIS; scores 20–40); fatigue, cognitive symptoms, pain, and sleep problems (0 −100 VAS); Time frame: baseline to Week 12

Abbreviations: BSI=Brief Symptom Inventory; CIS=Checklist Individual Strength; GW=Gulf War; GWI=Gulf War Illness; PRIME-MD=Primary Care Evaluation of Mental Disorders; SAT=Symptoms Assessment Tool; SCP=Specialized Care Program; SF-36=36-Item Short Form Health Survey

Table 15 Available results of unpublished randomized controlled trials of interventions for Gulf War Illness

| Electrical stimulation^57,70^ | Low-glutamate diet^25,41^ | Xylitol nasal irrigation^59^ | Yoga^39,62^
| Descriptive characteristics
N total | N=60 | N=17^*^ | N=40 | N=68 (treated)
N per arm | Electrical stimulation (stochastic noise) vs Sham electrical stimulation | Low- vs high-glutamate diet | Saline vs xylitol vs usual care: 14 vs 14 vs 12 | Yoga vs CBT: 37 vs 31
Duration of treatment and observation | Tx and Obs: 12 weeks | Tx and Obs: 1 month | Tx: 8 weeks; Obs: 26 weeks | Tx: 10 weeks; Obs: 6 months
Demographics | NR | 12% Female; Age: 50 (4) | 20% Female; Age: 53.8 (SD 7.8); Race: 77.5% non-Hispanic White; 10% White Hispanic; 5% AA/Black; 2.5% Asian; 2.5% Pacific Islander/Hawaiian; 2.5% multiple races Educ: 7.5% high school or less | NR
| | Findings (change from baseline), Treatment vs Comparator
Pain | --- | | --- | BPI-SF pain (within group mean ± SD); [underlined: End-of-treatment]; Yoga: pre- 5.44 ± 2.00 vs post- 4.00 ± 2.08; P < 0.001; CBT: pre- 5.09 ± 1.62 vs post- 4.95 ± 2.35; P > 0.05; [underlined: 6-month f/u pain:]; Yoga: 4.70 ± 2.17; P=0.02; CBT: NR
Fatigue | --- | | MFI score (mean (SD)):; [underlined: Week 8]:; Xylitol 0.6 (2.4) vs saline 0.9 (2.3) vs control 0.5 (2.5); [underlined: Week 26:] Xylitol 1.9 (2.8) vs saline −1.4 (2.4) vs control 10.4 (3.0) | ---
Mental Health | --- | Anxiety (GAD-7) (median (IQR)): reduced from 9 (13) to 5 (10); P=0.01^*^ | --- | ---
PTSD | --- | PCL-C score (median (IQR)): reduced from of 58 (33) to 43 (28); P=0.04^*^ | --- | ---
Respiratory | --- | | SNOT-20 score (mean (SD)): [underlined: Week 8]:; Xylitol −16.9 (4.9) vs saline −8.8 (5.0) vs control −3.4 (5.3); [underlined: Week 26:]; Xylitol −18.9 (4.9) vs saline −16.9 (5.3) vs control −3.5 (5.6) | ---
Vestibular function | Ocular torsion (OT): improved in 53% of pts; mean increases of 25% (range 1–81); Sway: improved in 100% of participants; reduced by mean of 42% (Range 21–63).
Adverse events | NR | NR | No AEs or SAEs | NR

* Preliminary results, study ongoing

Abbreviations: AA=African American; BPI-SF=Brief Pain Inventory-Short Form; CBT=Cognitive Behavioral Therapy; GAD-7=Generalized Anxiety Disorder 7-item; IQR=Interquartile Range; MFI=Multidimensional Fatigue Inventory; NI=Nasal Irrigation; NR=Not Reported; Obs=Observation; PCL-C=PTSD Checklist – Civilian version; PTSD=Posttraumatic Stress Disorder; SAT=Symptoms Assessment Tool; SD=Standard Deviation; SNOT-20: Sinonasal Outcome Test-20

Table 16 Results of single-arm studies of interventions/management strategies for Gulf War Illness

Intervention | Specialized Care Program^29^ (Multicomponent group program)^a^ | KPAX002^50^ (Nutrient formula plus methylphenidate)
Descriptive characteristics
Total N | N=109 | N=15
Duration of treatment and total observation | Tx: 3 weeks; Obs: 1 & 3 months | Tx and Obs: 12 weeks
Demographics | 18.3% Female; Age: 56% younger than 40 years of age; Race: 50.5% White; 30.3% Black; 19.3% Others | 12% Female; Age: 53.0 (6.15); Race: 12% AA/Black, 6% Hispanic, 6% Native American, 71% white, 6% other
Findings (mean difference from baseline)
Physical Health Overall | SF-36 PCS; End-of-treatment (N=93): 1.08 (P=NS); 1-mo f/u (N=48): 0.96 (P=NS); 3-mo f/u (N=37): 1.49 (P=NS); No. of physical symptoms; End-of-treatment (N=102): −2.54 (P < 0.01); 1-mo f/u (N=51): −0.80 (0.01 < P < 0.05); 3-mo f/u (N=37): −1.14 (0.01 < P < 0.05) | ---
Fatigue | --- | CIS: −14 (±19.59) 95% CI, −22.3 to −5.7; P < 0.001; VAS: −1.3 (±2.41); P=0.019
GWI Symptoms Overall | --- | SAT: −8.8 (±12.54); 95% CI −13.2 to −4.5; P < 0.001
Mental Health Overall | SF-36 MCS; End-of-treatment (N=93): 5.17 (P < 0.01); 1-mo f/u (N=48): −0.69 (P=NS); 3-mo f/u (N=37): 0.70 (P= NS); Physical Health Concern (Whitely Index score): End-of-treatment (N=97): −0.65 (0.01 < P < 0.05); 1-mo f/u (N=49): −0.78 (P=NS); 3-mo f/u (N=37): −1.41 (P < 0.01) | ---
Psychosocial distress | Somatization score (BSI); End-of-treatment (N=97): −4.75 (P < 0.01); 1-mo f/u (N=49): −2.77 (P=NS); 3-mo f/u (N=37): −7.74 (0.01 < P < 0.05); Depression score (BSI); End-of-treatment (N=97): −3.05 (0.01 < P < 0.05); 1-mo f/u (N=49): 1.96 (P=NS); 3-mof/u (N=37): 1.38 (P=NS); Anxiety Score (BSI); End-of-treatment (N=97): −3.52 (P < 0.01); 1-mo f/u (N=49): −1.19 (P=NS); 3-mo f/u (N=37): −2.90 (P=NS) | ---
Other | --- | Sleep VAS: −1.4 (±2.47); P=0.026 Pain VAS: −1 (±2.62); P=0.054 Cognitive disturbance VAS: −1.5 (±2.45); P=0.006
Severe AEs/dropouts due to AEs | --- | No SAEs; 2 dropouts due to AEs

a An intensive outpatient program that included medical assessment and collaboration with providers and other GW Veterans in the development of an individualized symptom management plan combining primary medical care with exercise, self-care, and other active coping strategies.

Abbreviations: AA=African American; AE=Adverse Event; BSI=Brief Symptom Inventory; CIS=Checklist Individual Strength; F/U=Follow-up; MCS=Mental Component Summary; NS=Not Significant; P=P-value; PCS=Physical Component Summary; SAE=Severe Adverse Event; SAT=Symptoms Assessment Tool; SCP=Specialized Care Program; SF-36=36-Item Short Form Health Survey; Tx=Treatment; VAS=Visual Analog Scale