# APPENDIX C Quality Assessment Criteria

Cochrane Rob 2.0:^20^ Five domains through which bias may be introduced
1. Risk of bias arising from the randomization process:; 1.1 Was the allocation sequence random?; 1.2 Was the allocation sequence concealed until participants were enrolled and assigned to interventions?; 1.3 Did baseline differences between intervention groups suggest a problem with the randomization process?
2. Risk of bias due to deviations from the intended interventions (effect of assignment to intervention):; 2.1 Were participants aware of their assigned intervention during the trial?; 2.2 Were carers and people delivering the interventions aware of participants’ assigned intervention during the trial?; 2.3 If Y/PY/NI to 2.1 or 2.2: Were there deviations from the intended intervention that arose because of the experimental context?; 2.4 If Y/PY to 2.3: Were these deviations from intended intervention balanced between groups?; 2.5 If N/PN/NI to 2.4: Were these deviations likely to have affected the outcome?; 2.6 Was an appropriate analysis used to estimate the effect of assignment to intervention?; 2.7 If N/PN/NI to 2.6: Was there potential for a substantial impact (on the result) of the failure to analyse participants in the group to which they were randomized?
3. Risk of bias due to missing outcome data:; 3.1 Were data for this outcome available for all, or nearly all, participants randomized?; 3.2 If N/PN/NI to 3.1: Is there evidence that the result was not biased by missing outcome data?; 3.3 If N/PN to 3.2: Could missingness in the outcome depend on its true value?; 3.4 If Y/PY/NI to 3.3: Is it likely that missingness in the outcome depended on its true value?
4. Risk of bias in measurement of the outcome:; 4.1 Was the method of measuring the outcome inappropriate?; 4.2 Could measurement or ascertainment of the outcome have differed between intervention groups?; 4.3 If N/PN/NI to 4.1 and 4.2: Were outcome assessors aware of the intervention received by study participants ?; 4.4 If Y/PY/NI to 4.3: Could assessment of the outcome have been influenced by knowledge of intervention received?; 4.5 If Y/PY/NI to 4.4: Is it likely that assessment of the outcome was influenced by knowledge of intervention received?
5. Risk of bias in selection of the reported result:; 5.1 Were the data that produced this result analysed in accordance with a pre-specified analysis plan that was finalized before unblinded outcome data were available for analysis?; Is the numerical result being assessed likely to have been selected, on the basis of the results, from…; 5.2 …multiple outcome measurements (e.g. scales, definitions, time points) within the outcome domain?; 5.3 …multiple analyses of the data?
Overall risk-of-bias judgement
Low ROB | The study is judged to be at low risk of bias for all domains for this result.
Some Concerns | The study is judged to raise some concerns in at least 1 domain for this result, but not to be at high risk of bias for any domain.
High ROB | The study is judged to be at high risk of bias in at least one domain for this result.; OR; The study is judged to have some concerns for multiple domains in a way that substantially lowers confidence in the result.

Table 8 Risk of bias in trials of interventions for Gulf War Illness

Experimental intervention | Comparator | Randomization process | Deviations from intended interventions | Missing outcome data | Measurement of the outcome | Selection of the reported result | Overall Bias | Comment
Medications
Doxycycline^1^ | Placebo | Low | Low | Low | Low | Low | Low | ---
Mifepristone^2^ | Placebo | Low | Low | Low | Some concerns | Low | Some concerns | Analyzed completers only. Statistically underpowered: the intended sample size of 40 not reached due to recruitment difficulties.
Naltrexone^3^ | Placebo | Some concerns | Low | Low | High | High | High | Randomization and allocation concealment (cards drawn from box. Analyzed CGIS-responders vs non responders, not by randomization (Tx vs placebo).
Rifaximin^4^ | Placebo | Low | Some concerns | Low | Low | Low | Some concerns | Analyzed completers only.
Nutritional supplements
CoQ10^6^ | Placebo | Low | Low | Low | Low | High | High | Post-protocol changes in analytic approach; threshold/magnitude of change not defined for binary analyses of improvement.
Carnosine^5^ | Placebo | Low | Some concerns | High | Low | Low | High | Differential loss to follow-up: 37% vs 13.3% Analyzed completers only.
Psychological, exercise, and multi-component interventions
CBT + Exercise^7^ | TAU | Low | Low | Low | Some concerns | Low | Some concerns | Self-reported outcomes, subjects not blinded
Detox regimen^8^ | Waitlist | Some concerns | Low | Low | Some concerns | Low | Some concerns | Baseline differences in % disabled vs employed self-reported outcomes, subjects not blinded.
Mindfulness-based therapy^9^ | TAU | Low | Low | Low | Some concerns | Low | Some concerns | Self-reported outcomes, subjects not blinded.
Sleep-focused Mind-Body Therapy^10^ | Sleep education | Low | Low | Low | Some concerns | Low | Some concerns | Self-reported outcomes, subjects not blinded
Other interventions
Acupuncture (bi-weekly)^11^ | Waitlist/acupuncture (weekly) | Low | Some concerns | Low | Some concerns | Low | Some concerns | Self-reported outcomes; participants and intervention staff not blinded
CPAP^12^ | Sham CPAP | Low | Low | Low | Low | Low | Low | ---

Abbreviations: CBT=Cognitive Behavioral Therapy; CoQ10=Coenzyme Q10; CPAP=Continuous Positive Airway Pressure; IBS=Irritable Bowel Syndrome; MBB=Mind-body Bridging; MBSR=Mindfulness-based Stress Reduction; QoL=Quality of Life; ROB=Risk of Bias; SF-36=36-Item Short Form Health Survey; Sx=symptom; TAU=Treatment as Usual; Tx=Treatment; WAIS-R=Wechsler Adult Intelligence Scale-Revised.