# APPENDIX B Study Selection

## Inclusion codes, code definitions, and criteria

1. Is the full-text of the article in English?
  - Yes → Proceed to 2.
    No → Code X1 (Non-English-language publication). STOP.
2. Does the population include Veterans with Gulf War Illness?
  Include: Veterans (either U.S. or international) deployed to the Persian Gulf region between Aug 2, 1990 - Nov 1991, defined by the authors as having Gulf War Illness according to a recognized case definition (CDC or Kansas), or defines cases using similar criteria to CDC/Kansas, or using illness definitions prior to CDC/Kansas criteria (Chronic Multisymptom/multisystem) Illness (CMI), Irritable Bowel Syndrome (IBS), Chronic Fatigue Syndrome (CFS)/Myalgic Encephalitis(ME), fibromyalgia (FM), Gulf War Syndrome). Also include studies of civilian contractors present during the conflict, if available. Include studies where deployment status and/or time of deployment is unclear.
  - Yes → Proceed to 3.
    No → Code X2 (Excluded population). STOP.
3. Does the study examine the benefits and/or harms of an intervention or management strategy (pharmacological, supplement, non-pharmacological, behavioral, etc. – no exclusions) for treating symptoms of Gulf War Illness?
  - Yes → Proceed to 4.
    No → Is the study about a potential biomarker for GWI?
    - Yes → Code Biomarker. STOP.
      No → Code X3 (Not relevant to GWI interventions or biomarkers). STOP.
4. Is the study a published randomized controlled trial, non-randomized controlled trial, or cohort study that compares the intervention to placebo, usual care, or another active intervention, among Veterans with GWI?
  - Yes → Code Tx-KQ1-[specify intervention, specify condition if subset of GWI]. Proceed to 6.
  - No, compares GWI with a non-GWI population → Code X4 (non-GWI comparator). STOP.
  - No, it is a systematic review/meta-analysis of GWI interventions → Code Tx-SR. STOP.
  - No, it is a protocol/abstract/unpublished report that otherwise meets these criteria → Code Tx-KQ3 emerging research [specify intervention]. STOP.
  - No, for none of the reasons above → Proceed to 5.
5. Is the GWI intervention study a single-arm study or case series in which all participants received the same intervention for GWI?
  - Yes → Code Tx-KQ3 single-arm [specify intervention]. STOP.
    No → Code X5 (excluded study design or publication type). STOP.
  - Exclude: case studies, editorials, letters, and review articles that are non-systematic.
  - Mark “B” any X5’s that may contain useful content for background/discussion, eg:
    - B-X5 – Narrative review with good background
      B-X5 – May be useful for discussion
6. Does the study examine effectiveness or harms in a subgroup (defined by gender, symptom severity, case definition, or branch of military, as examples) compared with a larger population of Veterans with GWI?
  - Yes → Add code KQ2 (eg, Tx-KQ1–KQ2). STOP.
    No → STOP.

[underlined: Key Questions:]

1. Evidence on effectiveness/harms: What are the benefits and harms of pharmacological and non-pharmacological interventions and management strategies for Veterans with GWI?
2. Evidence about subgroups: Do the effectiveness or harms of the interventions/strategies differ among subgroups of Veterans with GWI, such as female Veterans or cases defined by specific criteria, in comparison with Veterans with GWI overall?
3. Emerging research: What interventions for GWI have been examined in
  a) noncomparative studies only?
  b) ongoing/unpublished trials or cohort studies?

[underlined: Exclusion Codes:]

- X1: Non-English-language publication
- X2: Excluded population
- X3: Not relevant to GWI interventions or biomarkers
- X4: Non-GWI comparator
- X5: Excluded study design or publication type
- X9: Duplicate or preliminary publication of a more recent study
- X99: Study terminated