# APPENDIX A Search Strategies

## Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily 1946 to September 16, 2019

Date searched: September 17, 2019

# | Searches | Results
1 | Persian Gulf Syndrome/ or Gulf War/ | 1069
2 | ((“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) adj7 (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab,kf. | 1044
3 | (“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab,kf. and (di or dg or dt or rt or rh or su or tu or th).fs. | 583
4 | (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab,kf. | 200
5 | (((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) adj7 (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or veteran*)) and (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab,kf. | 1566
6 | or/1–5 | 3087
7 | 6 not (“Enduring Freedom” or “Iran-Iraq” or “Iraq-Iran” or (Iraq adj2 Afghanistan) or “Iraqi Freedom” or OEF or OIF or “Op TELIC” or “Operation TELIC”).ti,ab,kf. | 1972
8 | 7 not ((exp animals/ not humans/) or (cat or cats or dog or dogs or mice or mouse or rat or rats or rodent).ti.) | 1849
9 | limit 8 to english language | 1809
10 | limit 9 to yr=“1990 -Current” | 1806

## EBM Reviews: Cochrane Central Register of Controlled Trials August 2019 Cochrane Database of Systematic Reviews 2005 to September 11, 2019

Date searched: September 17, 2019

# | Searches | Results
1 | ((“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) adj7 (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab. | 81
2 | (“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab. | 97
3 | (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab. | 45
4 | (((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) adj7 (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or veteran*)) and (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab. | 173
5 | or/1–4 | 264
6 | 5 not (“Enduring Freedom” or “Iran-Iraq” or “Iraq-Iran” or (Iraq adj2 Afghanistan) or “Iraqi Freedom” or OEF or OIF or “Op TELIC” or “Operation TELIC”).ti,ab. | 117

## PsycINFO 1806 to September Week 2 2019

Date searched: September 17, 2019

# | Searches | Results
1 | ((“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) adj7 (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab. | 375
2 | (“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”).ti,ab. | 1122
3 | (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”).ti,ab. | 57
4 | (((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) adj7 (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or veteran*)) and (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic adj (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) adj (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)).ti,ab. | 1314
5 | or/1–4 | 2310
6 | 5 not (“Enduring Freedom” or “Iran-Iraq” or “Iraq-Iran” or (Iraq adj2 Afghanistan) or “Iraqi Freedom” or OEF or OIF or “Op TELIC” or “Operation TELIC”).ti,ab. | 1318
7 | 6 not ((exp animals/ not humans/) or (cat or cats or dog or dogs or mice or mouse or rat or rats or rodent).ti.) | 1291
8 | limit 7 to english language | 1243
9 | limit 8 to yr=“1990 -Current” | 1242

## CINAHL with Full Text

Date searched: September 17, 2019

S1 | (MH “Persian Gulf Syndrome”) | 264
S2 | TI ( ((“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) N7 (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic N1 (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) N1 (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)) ) OR AB ( ((“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) N7 ((bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic N1 (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) N1 (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)) ) | 313
S3 | TI ( (“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) ) OR AB ( (“Desert Shield” or “Desert Storm” or “Gulf War” or “Gulf Conflict” or “Gulf Crisis” or “Kuwait War” or “Operation GRANBY” or “Op GRANBY”) ) | 629
S4 | TI ( (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”) ) OR AB ( (GWI or GWIs or GWVI or GWVIs or “Iowa Persian Gulf Study” or “War Related Illness and Injury Study Center*”) ) | 44
S5 | TI ( (veteran* N15 (“chronic fatigue” or fibromyalg* or “medically unexplained” or multisymptom or multi-symptom or multisystem or multi-system or myalgi* or ME/CFS)) ) OR AB ( (veteran* N15 (“chronic fatigue” or fibromyalg* or “medically unexplained” or multisymptom or multi-symptom or multisystem or multi-system or myalgi* or ME/CFS))) | 52
S6 | TI ( (((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) N7 (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or veteran*)) and (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic N1 (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) N1 (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)) ) OR AB ( (((Kuwait or Iraq or “Persian Gulf” or “Southwest Asia” or “SW Asia”) N7 (“air force” or “armed forces” or army or marines or “military personnel” or “national guard*” or naval or navy or “service members” or servicemembers or soldier* or veteran*)) and (bioassay* or bio-assay* or biomarker* or bio-marker* or CFS or (chronic N1 (fatigue or headache* or pain or “physical symptom*” or multisymptom or multi-symptom or multisystem or multi-system)) or cluster or cognit* or deployment or detect* or diagnos* or disease* or disorder* or expos* or fibromyalgi* or “functional somatic syndrome*” or gastrointestinal or gastro-intestinal or headache* or identif* or illness or “irritable bowel syndrome*” or ME?CFS or “medically unexplained” or “multiple chemical sensitivit*” or musculoskeletal or musculo-skeletal or myalgi* or neurocognit* or neuro-cognit* or neuropsych* or neuro-psych* or ((nonspecific or non-specific) N1 (“chest pain*” or symptom*)) or psychosomatic or pulmonar* or respirator* or sickness or syndrome or somatization or somatoform or temporomandibular or temporo-mandibular or therap* or treat* or war-related)) ) | 804
S7 | S1 OR S2 OR S3 OR S4 OR S5 OR S6 | 1,434
S8 | S7 NOT (“Enduring Freedom” or “Iran-Iraq” or “Iraq-Iran” or (Iraq N2 Afghanistan) or “Iraqi Freedom” or OEF or OIF or “Op TELIC” or “Operation TELIC”); Limiters –; Published Date: 19900101-20191231;; English Language;; Exclude MEDLINE records;; Human | 167

## Scopus

Date searched: September 17, 2019

TITLE-ABS-KEY ( “Desert Shield” OR “Desert Storm” OR “Gulf War” OR “Gulf Conflict” OR “Gulf Crisis” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY” OR “Iowa Persian Gulf Study” OR “War Related Illness and Injury Study Center” ); AND DOCTYPE ( cp ); AND PUBYEAR > 1989; AND ( LIMIT-TO ( LANGUAGE , “English” ) ); = 308 results

## Allied and Complementary Medicine (AMED)

Date searched: October 1, 2019

# | Searches | Results
S8 | S6 NOT S7 Limiters - Published Date: 19900101-20200131; Language: English | 55
S7 | TI (cat OR cats OR dog OR dogs OR mice OR mouse OR rat OR rats OR rodent) | 7,158
S6 | S4 NOT S5 | 58
S5 | TI (“Enduring Freedom” OR “Iran-Iraq” OR “Iraq-Iran” OR (Iraq N2 Afghanistan) OR “Iraqi Freedom” OR OEF OR OIF OR “Op TELIC” OR “Operation TELIC”) OR AB (“Enduring Freedom” OR “Iran-Iraq” OR “Iraq-Iran” OR (Iraq N2 Afghanistan) OR “Iraqi Freedom” OR OEF OR OIF OR “Op TELIC” OR “Operation TELIC”) | 191
S4 | S1 OR S2 OR S3 | 116
S3 | TI (((Kuwait OR Iraq OR “Persian Gulf” OR “Southwest Asia” OR “SW Asia”) N7 (“air force” OR “armed forces” OR army OR marines OR “military personnel” OR “national guard*” OR naval OR navy OR “service members” OR servicemembers OR soldier* OR veteran*)) AND (bioassay* OR bio-assay* OR biomarker* OR bio-marker* OR CFS OR (chronic N1 (fatigue OR headache* OR pain OR “physical symptom*” OR multisymptom OR multi-symptom OR multisystem OR multi-system)) OR cluster OR cognit* OR deployment OR detect* O … | 74
S2 | TI (GWI OR GWIs OR GWVI OR GWVIs OR “Iowa Persian Gulf Study” OR “War Related Illness and Injury Study Center*”) OR AB (GWI OR GWIs OR GWVI OR GWVIs OR “Iowa Persian Gulf Study” OR “War Related Illness and Injury Study Center*”) | 7
S1 | TI ((“Desert Shield” OR “Desert Storm” OR “Gulf War” OR “Gulf Conflict” OR “Gulf Crisis” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY”) N7 (bioassay* OR bio-assay* OR biomarker* OR bio-marker* OR CFS OR (chronic N1 (fatigue OR headache* OR pain OR “physical symptom*” OR multisymptom OR multi-symptom OR multisystem OR multi-system)) OR cluster OR cognit* OR deployment OR detect* OR diagnos* OR disease* OR disorder* OR expos* OR fibromyalgi* OR “functional somatic syndrome*” OR gastrointest … | 45

## ClinicalTrials.gov

Date searched: September 17, 2019

OTHER TERMS: “Desert Shield” OR “Desert Storm” OR “Gulf War” OR “Gulf Conflict” OR “Gulf Crisis” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY” OR “Iowa Persian Gulf Study” OR “War Related Illness and Injury Study Center”; = 71 results

## WHO ICTRP

Date searched: September 17, 2019

TITLE: “Desert Shield” OR “Desert Storm” OR “Gulf War” OR “Gulf Conflict” OR “Gulf Crisis” OR “Kuwait War” OR “Operation GRANBY” OR “Op GRANBY” OR “Iowa Persian Gulf Study” OR “War Related Illness and Injury Study Center”; RECRUITMENT STATUS=ALL; DATE OF REGISTRATION= 01/01/1990 – 17/09/2019; = 56 results