# References

1 Giacobbi PR, Jr., Stewart J, Chaffee K, Jaeschke A-M, Stabler M, Kelley GA. A Scoping Review of Health Outcomes Examined in Randomized Controlled Trials Using Guided Imagery. Progress in preventive medicine (New York, NY). 2017;2(7):e0010.
2 King K. A review of the effects of guided imagery on cancer patients with pain. Complementary Health Practice Review. 2010;15(2):98–107.
3 Zech N, Hansen E, Bernardy K, Hauser W. Efficacy, acceptability and safety of guided imagery/hypnosis in fibromyalgia - A systematic review and meta-analysis of randomized controlled trials. European journal of pain (London, England). 2017;21(2):217–227.
4 Woodford H, Price C. EMG biofeedback for the recovery of motor function after stroke. The Cochrane database of systematic reviews. 2007(2):CD004585.17443550
5 Greenhalgh J, Dickson R, Dundar Y. Biofeedback for hypertension: a systematic review. Journal of hypertension. 2010;28(4):644–652.20090553
6 Coulter ID, Favreau JT, Hardy ML, Morton SC, Roth EA, Shekelle P. Biofeedback interventions for gastrointestinal conditions: a systematic review. Alternative therapies in health and medicine. 2002;8(3):76–83.
7 Schoenberg PLA, David AS. Biofeedback for psychiatric disorders: a systematic review. Applied psychophysiology and biofeedback. 2014;39(2):109–135.24806535
8 Fisch S, Brinkhaus B, Teut M. Hypnosis in patients with perceived stress - a systematic review. BMC complementary and alternative medicine. 2017;17(1):323.28629342
9 Miake-Lye IM, Hempel S, Shanman R, Shekelle PG. What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Syst Rev. 2016;5:28.26864942
10 McGowan J, Sampson M, Salzwedel DM, Cogo E, Foerster V, Lefebvre C. PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. Journal of clinical epidemiology. 2016;75:40–46.27005575
11 Wallace B. Abstrackr: Open-source, Web-based Software for (Semi-automated?!) Abstract-screening. 2012;2018(April 17).
12 Shea BJ, Grimshaw JM, Wells GA, . Development of AMSTAR: a measurement tool to assess the methodological quality of systematic reviews. BMC medical research methodology. 2007;7:10.17302989
13 Nestoriuc Y, Martin A, Rief W, Andrasik F. Biofeedback treatment for headache disorders: a comprehensive efficacy review. Applied psychophysiology and biofeedback. 2008;33(3):125–140.18726688
14 Stanton R, Ada L, Dean CM, Preston E. Biofeedback improves activities of the lower limb after stroke: a systematic review. Journal of physiotherapy. 2011;57(3):145–155.21843829
15 Gordt K, Gerhardy T, Najafi B, Schwenk M. Effects of Wearable Sensor-Based Balance and Gait Training on Balance, Gait, and Functional Performance in Healthy and Patient Populations: A Systematic Review and Meta-Analysis of Randomized Controlled Trials. Gerontology. 2018;64(1):74–89.29130977
16 Ernst E, Kanji N. Autogenic training for stress and anxiety: a systematic review. Complementary therapies in medicine. 2000;8(2):106–110.10859603
17 Coelho HF, Canter PH, Ernst E. The effectiveness of hypnosis for the treatment of anxiety: A systematic review. Primary Care & Community Psychiatry. 2008;12(2):49–63.
18 Chen P-Y, Liu Y-M, Chen M-L. The Effect of Hypnosis on Anxiety in Patients With Cancer: A Meta-Analysis. Worldviews on evidence-based nursing. 2017;14(3):223–236.28267893
19 Cheseaux N, de Saint Lager AJ, Walder B. Hypnosis before diagnostic or therapeutic medical procedures: a systematic review. The International journal of clinical and experimental hypnosis. 2014;62(4):399–424.25084616
20 Giacobbi PR, Jr., Stabler ME, Stewart J, Jaeschke A-M, Siebert JL, Kelley GA. Guided Imagery for Arthritis and Other Rheumatic Diseases: A Systematic Review of Randomized Controlled Trials. Pain management nursing : official journal of the American Society of Pain Management Nurses. 2015;16(5):792–803.26174438
21 Cardoso JR, Teixeira EC, Moreira MD, Favero FM, Fontes SV, Bulle de Oliveira AS. Effects of exercises on Bell’s palsy: systematic review of randomized controlled trials. Otology & neurotology : official publication of the American Otological Society, American Neurotology Society [and] European Academy of Otology and Neurotology. 2008;29(4):557–560.
22 Jokubauskas L, Baltrusaityte A. Efficacy of biofeedback therapy on sleep bruxism: A systematic review and meta-analysis. Journal of oral rehabilitation. 2018.
23 Roffe L, Schmidt K, Ernst E. A systematic review of guided imagery as an adjuvant cancer therapy. Psycho-oncology. 2005;14(8):607–617.15651053
24 Cramer H, Lauche R, Paul A, Langhorst J, Kummel S, Dobos GJ. Hypnosis in breast cancer care: a systematic review of randomized controlled trials. Integrative cancer therapies. 2015;14(1):5–15.25233905
25 Casida J, Lemanski SA. An evidence-based review on guided imagery utilization in adult cardiac surgery. Clinical Scholars Review. 2010;3(1):22–30.
26 Woodward S, Norton C, Chiarelli P. Biofeedback for treatment of chronic idiopathic constipation in adults. The Cochrane database of systematic reviews. 2014(3):CD008486.24668156
27 Hadjibalassi M, Lambrinou E, Papastavrou E, Papathanassoglou E. The effect of guided imagery on physiological and psychological outcomes of adult ICU patients: A systematic literature review and methodological implications. Australian critical care : official journal of the Confederation of Australian Critical Care Nurses. 2018;31(2):73–86.28365068
28 Sado M, Ota E, Stickley A, Mori R. Hypnosis during pregnancy, childbirth, and the postnatal period for preventing postnatal depression. The Cochrane database of systematic reviews. 2012(6):CD009062.22696381
29 Benfield JK, Everton LF, Bath PM, England TJ. Does therapy with biofeedback improve swallowing in adults with dysphagia? A systematic review and meta-analysis. Archives of physical medicine and rehabilitation. 2018.
30 Vonthein R, Heimerl T, Schwandner T, Ziegler A. Electrical stimulation and biofeedback for the treatment of fecal incontinence: a systematic review. International journal of colorectal disease. 2013;28(11):1567–1577.23900652
31 Glombiewski JA, Bernardy K, Hauser W. Efficacy of EMG- and EEG-Biofeedback in Fibromyalgia Syndrome: A Meta-Analysis and a Systematic Review of Randomized Controlled Trials. Evidence-based complementary and alternative medicine : eCAM. 2013;2013:962741.24082911
32 Greenhalgh J, Dickson R, Dundar Y. The effects of biofeedback for the treatment of essential hypertension: a systematic review. Health technology assessment (Winchester, England). 2009;13(46):1–104.
33 Nesrallah GE, Suri RS, Guyatt G, . Biofeedback dialysis for hypotension and hypervolemia: a systematic review and meta-analysis. Nephrology, dialysis, transplantation : official publication of the European Dialysis and Transplant Association - European Renal Association. 2013;28(1):182–191.
34 Lam T-H, Chung K-F, Yeung W-F, Yu BY-M, Yung K-P, Ng TH-Y. Hypnotherapy for insomnia: a systematic review and meta-analysis of randomized controlled trials. Complementary therapies in medicine. 2015;23(5):719–732.26365453
35 Schaefert R, Klose P, Moser G, Hauser W. Efficacy, tolerability, and safety of hypnosis in adult irritable bowel syndrome: systematic review and meta-analysis. Psychosomatic medicine. 2014;76(5):389–398.24901382
36 Richards R, van den Noort JC, Dekker J, Harlaar J. Gait Retraining With Real-Time Biofeedback to Reduce Knee Adduction Moment: Systematic Review of Effects and Methods Used. Archives of physical medicine and rehabilitation. 2017;98(1):137–150.27485366
37 Barragan Loayza IM, Sola I, Juando Prats C. Biofeedback for pain management during labour. The Cochrane database of systematic reviews. 2011(6):CD006168.21678353
38 Madden K, Middleton P, Cyna AM, Matthewson M, Jones L. Hypnosis for pain management during labour and childbirth. Cochrane Database of Systematic Reviews. 2016(5):CD009356.27192949
39 Kim S-D. Psychological effects of yoga nidra in women with menstrual disorders: A systematic review of randomized controlled trials. Complementary therapies in clinical practice. 2017;28:4–8.28779936
40 Milling LS, Gover MC, Moriarty CL. The effectiveness of hypnosis as an intervention for obesity: A meta-analytic review. Psychology of Consciousness: Theory, Research, and Practice. 2018;5(1):29–45.
41 Bowker E, Dorstyn D. Hypnotherapy for disability-related pain: A meta-analysis. Journal of health psychology. 2016;21(4):526–539.24788104
42 Kanji N, White AR, Ernst E. Autogenic training for tension type headaches: a systematic review of controlled trials. Complementary therapies in medicine. 2006;14(2):144–150.16765853
43 Posadzki P, Ernst E. Guided imagery for musculoskeletal pain: a systematic review. The Clinical journal of pain. 2011;27(7):648–653.21430523
44 Mirelman A, Maidan I, Deutsch JE. Virtual reality and motor imagery: promising tools for assessment and therapy in Parkinson’s disease. Movement disorders : official journal of the Movement Disorder Society. 2013;28(11):1597–1608.24132848
45 Rotaru T-S, Rusu A. A Meta-Analysis for the Efficacy of Hypnotherapy in Alleviating PTSD Symptoms. The International journal of clinical and experimental hypnosis. 2016;64(1):116–136.26599995
46 Karavidas MK, Tsai P-S, Yucha C, McGrady A, Lehrer PM. Thermal biofeedback for primary Raynaud’s phenomenon: a review of the literature. Applied psychophysiology and biofeedback. 2006;31(3):203–216.17016765
47 Izquierdo de Santiago A, Khan M. Hypnosis for schizophrenia. (6).
48 Barnes J, Dong CY, McRobbie H, Walker N, Mehta M, Stead LF. Hypnotherapy for smoking cessation. The Cochrane database of systematic reviews. 2010(10):CD001008.20927723
49 Li R-Q, Li Z-M, Tan J-Y, Chen G-L, Lin W-Y. Effects of motor imagery on walking function and balance in patients after stroke: A quantitative synthesis of randomized controlled trials. Complementary therapies in clinical practice. 2017;28:75–84.28779941
50 Hsu L-F, Liao Y-M, Lai F-C, Tsai P-S. Beneficial effects of biofeedback-assisted pelvic floor muscle training in patients with urinary incontinence after radical prostatectomy: A systematic review and metaanalysis. International journal of nursing studies. 2016;60:99–111.27297372
51 Herderschee R, Hay-Smith EJC, Herbison GP, Roovers JP, Heineman MJ. Feedback or biofeedback to augment pelvic floor muscle training for urinary incontinence in women. The Cochrane database of systematic reviews. 2011(7):CD009252.21735442
52 Kapogiannis A, Tsoli S, Chrousos G. Investigating the Effects of the Progressive Muscle Relaxation-Guided Imagery Combination on Patients with Cancer Receiving Chemotherapy Treatment: A Systematic Review of Randomized Controlled Trials. Explore (New York, NY). 2018;14(2):137–143.
53 Stanton R, Ada L, Dean CM, Preston E. Biofeedback improves performance in lower limb activities more than usual therapy in people following stroke: a systematic review. Journal of physiotherapy. 2017;63(1):11–16.27989731
54 McPheeters M, Butler M, Maglione M, . AHRQ Methods for Effective Health Care. Challenges in Conducting EPC Reviews of Behavior Change Interventions. 2015.
55 Hrobjartsson A, Emanuelsson F, Skou Thomsen AS, Hilden J, Brorson S. Bias due to lack of patient blinding in clinical trials. A systematic review of trials randomizing patients to blind and nonblind sub-studies. International journal of epidemiology. 2014;43(4):1272–1283.24881045
56 Milling LS, Reardon JM, Carosella GM. Mediation and moderation of psychological pain treatments: response expectancies and hypnotic suggestibility. J Consult Clin Psychol. 2006;74(2):253–262.16649870
57 Berkman N, Lohr K, Ansari M, . Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. Rockville, MD: Agency for Healthcare Research and Quality; Methods Guide for Comparative Effectiveness Reviews (AHRQ Publication No. 13(14)-EHC130-EF);2013.