# Summary and Discussion

These evidence maps provide a broad overview of the evidence base regarding guided imagery, biofeedback, and hypnosis interventions. We systematically searched the literature for systematic reviews and meta-analyses of these interventions, and we included 40 good-quality systematic reviews examining these interventions across a variety of targeted health conditions. We compiled evidence maps to illustrate the reported effects of each intervention in the populations studied. Figure 6 on the following page shows the health conditions for which the interventions that were found to have either a consistently positive effect for any outcome, or consistent evidence of no effect; findings of potential or unclear effectiveness are not shown in Figure 6.

Biofeedback was the best studied intervention both in terms of the absolute size of the literature, and in terms of the overall level of confidence in findings. In particular, there was moderate to high level confidence that biofeedback is likely to be effective for urinary incontinence after prostatectomy, fecal incontinence, balance and gait in stroke patients, and headache. Indeed, the finding that biofeedback may improve global health outcomes in headache (both migraine and tension-type) and for urinary incontinence after prostatectomy (as an adjunct to pelvic floor muscle training) further underscores these as particularly promising areas for intervention.

The only other intervention for which there was evidence of effectiveness supported by at least moderate level confidence was guided imagery in the treatment of patients with arthritis or other rheumatic diseases (Figure 6).

The level of confidence for the majority of outcomes for most of the health conditions that were included was low or insufficient, which suggests that further research in these areas is very likely to appreciably change our understanding of the effectiveness of these interventions. The most common reasons the level of confidence was inadequate were a limited number of trials/small combined sample sizes and methodologic limitations in the included RCTs. Of note, the reviews included in this report generally provide very little insight into the impact of these interventions on global outcomes such as quality of life and functional status.

## Limitations

Because these evidence maps provide a broad overview of the existing evidence compiled by systematic reviews, they cannot be definitive in determining an absence of evidence. Many conditions for which these therapies have been utilized do not appear on the maps at all due to the lack of quality evidence syntheses. Because we relied on existing systematic reviews and did not perform a comprehensive search for primary trials, it is possible that more recent evidence is available, or that the interventions of interest have been tested in populations not represented in existing systematic reviews. Another potential limitation is that we included systematic reviews that focused specifically on the interventions of interest, and excluded systematic reviews that examined multiple treatments for a particular health condition. We attempted to mitigate potential loss of information by comparing the findings and included trials from more broadly scoped reviews with those of the more narrowly focused systematic reviews that we included. Finally, in regard to biofeedback, the use of systematic reviews meant that in many cases we were not able to distinguish the different types of biofeedback modalities, and were therefore unable to evaluate the utility of specific types of biofeedback. There may be evidence that some types but not others are effective for various conditions, but the evidence map format of this review precluded our ability to elucidate that level of granularity.

Figure 6 Evidence map of the health conditions for which guided imagery, biofeedback, and hypnosis interventions had evidence of a positive effect or evidence of no effect

The authors of the included reviews often noted lack of patient blinding, which is not surprising given the nature of the interventions. The role and necessity of patient blinding in studies of these types of interventions has been debated. There are techniques even for complex nonpharmacologic interventions to blind patients to some degree.^54^ Some argue that lack of patient blinding in trials of non-pharmacologic therapies may considerably exaggerate treatment effects;^55^ in which case, it would be difficult to determine whether and to what extent positive treatment effects – especially for the findings with only low level confidence – were due to an independent effect of treatment, expectancy as a mechanism of change, placebo effect, or a combination of these factors. On the other hand, others have argued that blinding is not only challenging but also potentially counterproductive as expectancy for change is thought to be an integral part of the intervention itself.^56^

The decision about which conditions to implement these interventions in VA is a policy-level one that depends in part on consideration of the evidence regarding benefits and harms, as well as an understanding of the costs of the intervention, and patients’ values and preferences. These maps provide only broad “brushstrokes” regarding the potential benefits of these interventions. Evidence maps such as these are not designed to provide definitive conclusions about benefit, and there are several reasons for cautious interpretation: 1) we relied only on systematic reviews and did not search for more recently published trials, 2) we cannot comment on the magnitude of treatment effect, 3) we relied on others’ study quality assessments, and 4) our measure of the level of confidence cannot approach the rigor represented by standardized approaches^57^ given the previously listed constraints. One should be particularly circumspect about the “potential for positive effect” findings since these were – by design – weighted toward identifying any potential area of benefit to aid with research prioritization.

Unfortunately, we have very little data from these reviews regarding harms as they were almost uniformly poorly reported. On the other hand, from a clinical and biologic plausibility standpoint, it is unlikely that these 3 interventions are associated with clinically significant harms.

## Research Gaps/Future Research

As stated above, the maps highlight many potential areas for future research. The interventions and health conditions for which there was evidence of a “potential positive effect” may be one place to start to prioritize research, since these findings may represent mixed findings across multiple outcomes. However, these specific conditions likely underscore potentially fruitful areas of research. Future studies should be designed to allow for patient blinding,^55^ as this was a common and important weakness in much of the literature.

## Conclusions

Of the 3 interventions, biofeedback was the most widely studied, and there was moderate- to high-level confidence that biofeedback is beneficial for urinary incontinence after prostatectomy, fecal incontinence, balance and gait in stroke patients, and headache. There was a moderate level of confidence that guided imagery has positive effects in the treatment of patients with arthritis or other rheumatic diseases. Positive effects were reported with hypnosis on obesity, anxiety in patients with cancer, and symptoms during breast cancer treatment, but the levels of confidence in these findings were low.