# Results

## Literature Flow

Our search of electronic databases, bibliographies, and other sources resulted in a total of 2,533 citations. After reviewing titles and abstracts, we included 229 for further screening at the full-text level. Of these, 93 systematic reviews met our inclusion criteria. From those 93 systematic reviews we selected 40 representing the most recent and comprehensive evidence available on each intervention, as applied to distinct medical conditions and target populations (Figure 2).

Table 3 lists the target populations examined in the systematic reviews that met our inclusion criteria, according to treatment modality. Biofeedback interventions were studied in the largest number of health conditions and target populations (N=16), followed by hypnosis (N=14), and guided imagery (N=12). Pain conditions and various forms of anxiety were among the most widely represented. All 3 interventions were studied in patients with fibromyalgia. The findings of each systematic review are provided in Appendix D.

The health conditions for which guided imagery, biofeedback, and hypnosis interventions have been researched are not listed comprehensively in Table 3. Evidence from clinical trials may be available for health conditions not listed, or for additional treatment modalities within the health conditions listed. For example, a systematic review of heart rate variability (HRV) biofeedback for anxiety occurred in our literature search but did not meet our inclusion criteria, and is therefore not represented in Table 3 or in the evidence maps that follow. Although there is research using HRV biofeedback and EEG biofeedback for ADHD, the studies on ADHD and biofeedback that were captured in our literature search did not meet our inclusion criteria.

Figure 2 Literature Flow Chart

*2 SRs addressed both KQ1 and KQ3.

Abbreviations: EBM = evidence-based medicine; KQ = key question; SR = systematic review

Table 3 Medical conditions and target populations studied in systematic reviews of guided imagery, biofeedback, and hypnosis

Condition/population | Number of controlled trials (N=participants combined) | | | Total trials | Total pts
Condition/population | Guided Imagery (12 SRs) | Biofeedback (16 SRs) | Hypnosis (14 SRs) | Total trials | Total pts
Anxiety | 2 (N=44)^16^ | | 14 (N=653)^17^ | 16 | 697
Anxiety, cancer | | | 20 (N=878)^18^ | 20 | 878
Anxiety, medical procedures | | | 18 (N=968)^19^ | 18 | 968
Arthritis/rheumatic disease | 7 (N=207)^20^ | | | 7 | 207
Balance/Gait training | | 8 (N=243)^15^ | | 8 | 243
Bell’s Palsy | | 4 (N=118)^21^ | | 4 | 118
Bruxism, sleep | | 6 (N=126) ^22^ | | 6 | 126
Cancer | 4 (N=199)^23^ | | | 4 | 199
Cancer, breast | | | 13 (N=1357) ^24^ | 13 | 1357
Cardiac surgery | 6 (N=433)^25^ | | | 6 | 433
Chronic idiopathic constipation | | 17 (N=931)^26^ | | 17 | 931
Critical illness/intensive care | 10 (N=1363)^27^ | | | 10 | 1363
Depression, postnatal | | | 1 (N=63) ^28^ | 1 | 63
Dysphagia | | 5 (N=141)^29^ | | 5 | 141
Fecal incontinence | | 12 (N=350)^30^ | | 12 | 350
Fibromyalgia | 4 (N=240)^3^ | 7 (N=321)^31^ | 5 (N=388)^3^ | 16 | 949
Hypertension | | 36 (N=1660)^32^ | | 36 | 1660
Intradialytic hypotension | | 8 (N=716) ^33^ | | 8 | 716
Insomnia | 6 (N=284)^34^ | | 6 (N=218)^34^ | 12 | 502
Irritable bowel syndrome | | | 8 (N=464)^35^ | 8 | 464
Knee osteoarthritis/Gait training | | 1 (N=56)^36^ | | 1 | 56
Labor/childbirth | | 4 (N=186) ^37^ | 9 (N=2954) ^38^ | 13 | 3140
Menstrual disorders | 2 (N=250)^39^ | | | 2 | 250
Obesity/weight loss | | | 10 (N=882)^40^ | 10 | 882
Pain, disability-related | | | 10 (N=380) ^41^ | 10 | 380
Pain, headache | 7 (N=400)^42^ | 94 (N=3500) ^13^ | | 101 | 3900
Pain, musculoskeletal | 9 (N=325)^43^ | | | 9 | 325
Parkinson’s | 2 (N=60)^44^ | | | 2 | 60
PTSD | | | 5 (N=383) ^45^ | 5 | 383
Raynaud’s | | 10 (N=5 31)^46^ | | 10 | 531
Schizophrenia | | | 3 (N=149)^47^ | 3 | 149
Smoking cessation | | | 11 (N=1120) ^48^ | 11 | 1120
Stroke | 17 (N=735)^49^ | 18 (N=429)^14^ | | 35 | 1164
Urinary incontinence after prostatectomy | | 13 (N=1108)^50^ | | 13 | 1108
Urinary incontinence in women | | 22 (N=1361)^51^ | | 22 | 1361

Abbreviations: pts = participants; PTSD = posttraumatic stress disorder; SR = systematic review

## KEY QUESTION 1 In which populations has guided imagery been examined, and what is the evidence of effectiveness and harms in each of these populations?

### Summary of Findings

We identified 12 systematic reviews examining the effectiveness of guided imagery interventions for anxiety, arthritis, cancer, cardiac surgery, ICU patients, fibromyalgia, headache, menstrual disorders, musculoskeletal pain, Parkinson’s disease, and stroke. The systematic reviews varied in the scope of interventions they defined as guided imagery. Patients with arthritis/rheumatic diseases experienced positive effects on pain symptoms and the confidence in the evidence was moderate. Possible benefits were reported in several of the other populations studied, but the findings were mixed and the level of confidence in the evidence was low overall.

### Detailed Findings

We included 12 systematic reviews of guided imagery interventions. Guided imagery interventions were most commonly delivered using pre-recorded scripts on audio or video tapes, though some studies also used in-person sessions. We found 1 systematic review of yoga nidra as a form of guided imagery.^39^

The systematic reviews varied in the scope of interventions they defined as guided imagery. Our search strategy included motor imagery, while a systematic review of guided imagery for musculoskeletal pain excluded motor imagery.^43^ Although some trials combined guided imagery with relaxation techniques, we excluded a systematic review of progressive muscle relaxation (PMR) combined with guided imagery in cancer patients because PMR was the predominant intervention in some the included trials.^52^ In our initial literature yield, there were 2 systematic reviews that included mirror therapy and virtual reality interventions as forms of guided imagery. Because we defined guided imagery as excluding externally driven processes or externally derived images, we excluded virtual reality and mirror therapy.

Figure 3 shows the effects of guided imagery in the 12 populations studied. Evidence of a positive effect was found for outcomes on 2 of the studied conditions: pain in patients with arthritis/rheumatic disease, and secondary outcomes (anxiety and depression) in cancer patients.

Patients with arthritis or rheumatic diseases^20^ experienced positive effects on pain (moderate confidence) with guided imagery, as well as potential positive effects on the secondary and global outcomes of anxiety, mobility, and quality of life (low level of confidence). Table 8 in Appendix D provides greater detail on the findings from systematic reviews of guided imagery.

Potential positive effect on diagnosis-related outcomes was found for 7 of the 12 targeted health conditions with a generally low level of confidence. (Table 5 in Appendix C). Cancer patients experienced reductions in anxiety and depression with guided imagery, and there was evidence of a potential positive effect on patient comfort during radiation/chemotherapy.^23^ The level of confidence in these findings was low.

Potentially positive effects on diagnosis-related outcomes, as well as anxiety and tension, for patients undergoing cardiac surgery were identified with a low level of confidence. For critically ill ICU patients there was also evidence of potentially positive effect on diagnosis-related outcomes, but evidence of no effect on a range of secondary outcomes (see Table 8 for more detail). The level of confidence in these findings was low.

In patients with fibromyalgia,^3^ while there was evidence of no effect on pain (4 studies, N=224), there were potential positive effects on secondary outcomes including psychological distress and coping with pain. The level of confidence for both outcomes was low.

Potential positive effects on diagnosis-related outcomes were also reported with guided imagery interventions in patients with stroke, Parkinson’s disease, and menstrual disorders (low level of confidence; Table 8 in Appendix D). The evidence of effect was unclear or insufficient in systematic reviews of patients with anxiety, headache, insomnia, and musculoskeletal pain.

Adverse effects of guided imagery were not reported in the systematic reviews identified in our search. The evidence on harms of guided imagery is insufficient.

With the exception of moderate confidence in the evidence for diagnosis-related outcomes in arthritis and rheumatic disease, the levels of confidence in the evidence on guided imagery were generally low, owing to heterogeneity among the intervention modalities, high risk of bias, lack of blinding, and limited generalizability in some of the populations studied (Table 5 in Appendix C).

Figure 3 Map of the evidence from systematic reviews of guided imagery interventions by clinical condition, evidence of effectiveness, and level of confidence

## KEY QUESTION 2 In which populations has biofeedback been examined, and what is the evidence of effectiveness and harms in each of these populations?

### Summary of Findings

We identified 16 systematic reviews examining the effectiveness of biofeedback alone or as an adjunct for a wide range of clinical conditions. There was clear, high-confidence evidence that biofeedback can reduce pain resulting from migraines and tension type headaches,^13^ and that as an adjunct to pelvic floor muscle training (PFMT) it can provide benefit to men experiencing urinary incontinence after a prostatectomy.^50^ There were also positive effects for stroke and fecal incontinence and the confidence in these findings was moderate. We found low-confidence evidence that biofeedback provides no benefit for women experiencing urinary incontinence,^51^ secondary or global outcomes for fibromyalgia patients,^31^ or hypertension.^32^ Overall, findings for other conditions were insufficient to form a conclusion.

### Detailed Findings

We identified 16 systematic reviews examining the effectiveness of biofeedback on primary/diagnosis-related outcomes, secondary outcomes, and global outcomes (eg, quality of life). The number of RCTs in the systematic reviews ranged from 1 (knee osteoarthritis)^36^ to 94 (headache),^13^ and included subjects ranged from 56^36^ to over 3,500^13^ (Table 3). Biofeedback modalities varied both within and by condition, as did the use of adjunctive interventions (Table 4). We also looked for evidence regarding heartrate variability biofeedback, but found no systematic reviews that met inclusion criteria. Across all reviews, 9 examined only primary diagnosis-related outcomes, 6 examined secondary outcomes, and 6 examined global outcomes (Table 9 in Appendix D).

For patients with migraine or tension-type headaches, there is consistent evidence of benefit in all 3 outcome categories. There was high-confidence evidence that biofeedback is effective for reducing the frequency, duration, and intensity of headache. Evidence of benefit on secondary outcomes such as medication intake, muscle tension, anxiety, and depression had a moderate-level of confidence. There was low-confidence evidence of improved self-efficacy.^13^

For men with urinary incontinence after prostatectomy, there is high-confidence evidence that biofeedback as an adjunct to PFMT can result in both immediate and long-term improvement compared to PFMT alone. There was moderate-confidence evidence that the addition of biofeedback had a positive effect on quality of life.^50^

For patients with stroke, there is moderate-confidence evidence that compared with usual care, the addition of biofeedback is more effective for short-term lower limb activity improvement, such as standing and walking.^14^.

For patients with fecal incontinence, electrical stimulation with biofeedback is more effective than electrical stimulation alone.^30^ The level of confidence in this finding is moderate (Figure 4; Table 9 in Appendix D).

We also identified low-confidence evidence of potential benefit in hemodialysis, fibromyalgia, and balance/gait training. In hemodialysis patients with chronic fluid overload or symptomatic intradialytic hypotension (IDH), there were potential benefits in reducing mortality and IDH.^33^ Among patients with fibromyalgia, electromyograph (EMG), but not electroencephalograph (EEG), biofeedback has potential benefit for pain, though no effects were observed on quality of life or secondary outcomes.^31^ Finally, wearable sensors may provide better static steady state balance and health-related quality of life outcomes for patients undergoing balance or gait training (Figure 4; Table 9 in Appendix D).^15^

Evidence suggests that biofeedback provides no benefit for urinary incontinence in women^51^ or for blood pressure control.^32^ Findings related to all other conditions were insufficient (Figure 4; Table 9 in Appendix D).

For 5 conditions (ie, fecal incontinence,^30^ urinary incontinence in women,^51^ dysphagia,^29^ stroke,^53^ and Bell’s palsy^21^) systematic reviews specifically examined biofeedback as an adjunct to another intervention. Five reviews examined the effectiveness of biofeedback independent of other interventions (ie, sleep bruxism,^22^ chronic idiopathic constipation,^26^ knee osteoarthritis,^36^ balance/gait training,^15^ and intradialytic hypotension^33^). For all other conditions, systematic reviews included studies examining biofeedback with or without another intervention (Table 4).^13,31,32,37,50^

Contributing to the confidence levels for diagnosis-related outcomes were small combined samples sizes, poor study quality, heterogeneity in adjunctive interventions, and inconsistencies across studies included in the systematic reviews. For secondary and global outcomes, sample sizes were all less than 500 (half of those reporting secondary outcomes were less than 100), and study quality was generally poor (Table 6 in Appendix C).

Table 4 Biofeedback techniques used and adjunctive therapies by health condition

Condition | Biofeedback techniques used | Adjunctive therapies
Balance/Gait training ^15^ | Wearable plantar pressure sensors (sensor which measures the distribution of plantar pressure, usually when standing or moving); IMU (inertial measurement unit: a type of sensor measuring velocity, acceleration, and direction of body movements) | ---
Bell’s Palsy ^21^ | Electromyography (EMG, also called Surface EMG or SEMG) - Sensors placed on the surface of the skin measure muscle tension; Biofeedback rehabilitation - “Method of biofeedback rehabilitation (patients tried to keep their eyes open symmetrically during 3 designated mouth movements using a mirror) for 30 min” | With mime therapy. Other therapies varied - facial expression exercises, lip movement without eye closure.
Chronic idiopathic constipation ^26^ | EMG biofeedback; Balloon sensory biofeedback - balloon is inserted into the rectum and used to measure amount of pressure exerted by muscles; Manometry biofeedback - sensors are used to measure pressure, usually used for urinary and fecal incontinence | ---
Dysphagia ^29^ | Surface electromyography, accelerometry, tongue manometry, video endoscopy, respiratory plethysmography, external laryngeal manometry:; [underlined: Accelerometry:] “This consists of a small accelerometer being placed just above the thyroid cartilage. It measures the epidermal vibrations caused by the internal sounds and vibrations of the superior/inferior and or anterior/posterior movements of the hyoid and larynx during swallowing. The vibrations are converted into a voltage signal, which the patient can use as visual feedback to facilitate their swallowing therapy”; [underlined: Tongue Manometry:] “This intervention consists of using an air-filled pressure bulb which acts as a pneumatic pressure sensor and measures isometric tongue strength. The bulb is placed on the tongue and the participant is instructed to push the tongue against the hard palate. The pressure generated is measured by a manometer and the signal can be displayed graphically on a screen to give patients biofeedback”; [underlined: External Laryngeal Manometry]: “an air-filled balloon fixed externally to the cervical region to measure changes in pressure during swallowing”; [underlined: Video Endoscopy]: “This involves the insertion of a flexible nasoendoscope to the level of the soft palate so that the pharynx and larynx can be visualized. The timing, safety and efficiency of the swallow can also be visualized and used for biofeedback”; [underlined: Respiratory Inductance Plethysmography]: “Nasal airflow is measured by a nasal cannula and respiratory inductance plethysmography measures movements of the ribcage and abdomen.” | With swallow therapy
Fecal Incontinence ^30^ | EMG biofeedback, balloon sensory biofeedback | With electrical stimulation
Fibromyalgia ^31^ | EMG biofeedback; [underlined: EEG] – also known as EEG biofeedback or neurofeedback- sensors placed on various points on the scalp measure brain wave activity which is fed back to the patient via a display, and the display is used to teach the patient self-regulation; [underlined: LENS] – “a combination of a conventional EEG and sub-threshold photic stimulation in order to change EEG patterns”; [underlined: Sensorimotor Rhythm Training (SMR]) – an EEG procedure that aims to facilitate thalamic inhibitory mechanisms” | Varied - PMR
Headache^13^ | TEMP biofeedback, TEMP + EMG biofeedback, EMG biofeedback, BVP biofeedback, EEG biofeedback, GSR biofeedback; Blood Volume Pulse (BVP) Biofeedback. BVP measures “heart rate based on the volume of blood that passes through tissue in a localized area with each beat (pulse) of the heart” | Varied - relaxation
Hypertension ^32^ | Indirect biofeedback – trains patient to identify and control any stress response that might lead to increased blood pressure; Direct biofeedback – direct feedback of blood pressure on a heartbeat from any blood pressure device | Varied - relaxation, meditation, imagery, inner quality management
Intradialytic hypotension ^33^ | Biofeedback hemodialysis: BVM with dialysate conductivity control, BVM with plasma conductivity-controlled BVM (relative blood volume monitoring).; [underlined: Biofeedback hemodialysis]: “biofeedback dialysis in which the primary input variable for the biofeedback algorithm was relative blood volume and in which dialysate conductivity was manipulated without directly measuring blood-side conductivity (eg, Hemocontrol™, Hospal-Gambro, Quebec, Canada).”; [underlined: BVM with plasma conductivity-controlled] “biofeedback dialysis in which plasma conductivity was measured directly (in the blood lines), and served as an input variable in the biofeedback algorithm, along with relative blood volume (eg, Diacontrol™, Hospal-Gambro)” | ---
Knee osteoarthritis/Gait retraining ^36^ | Visual, haptic (not specified) – feedback is delivered via visual system or haptic (touch) | ---
Labor pain ^37^ | EMG-electromyograph. A biofeedback technique in which sensors measure and feed back muscle tension, skin-conductance (the property of the human body that causes continuous variations in the electrical characteristics of the skin) (WIKIPEDIA); Also called galvanic skin response or electrodermal response – sensors measure the amount of sweat you produce (a measure of stress response) to measure the conductivity of your skin | Varied - relaxation, PMR, Lamaze
Raynaud’s ^46^ | Thermal biofeedback-TBF – biofeedback technique which measures skin temperature with the goal to train subjects to control peripheral vasoconstrictor responses and acquire voluntary hand warming skills.; Thermal feedback + EMG (biofeedback focused on measurement of skin temperature and muscle tension) | Varied - autogenic training, relaxation
Sleep bruxism ^22^ | Contingent electrical stimulation – electrical stimulation is delivered to the skin, lip, and masticatory muscles to interrupt the sleep cycle upon detection of grinding, clenching | ---
Stroke ^53^ | Weight distribution from a force platform or sensor, muscle activity from EMG, linear gait parameters from foot sensors, joint angle from a goniometer.; [underlined: Weight distribution from a force platform or sensor] – Force platform (or sensor) measures ‘ground reaction forces” generated by a body in motion or standing and quantifies various parameters including gait, weight distribution, gait, etc.; [underlined: Muscle activity from EMG] – as previously defined; [underlined: Linear gait parameters from foot sensors] – “parameters of gait patterns which included step length, width symmetry of feet, etc. which were fed back either visually or auditorily and measured when the patient was walking.”; [underlined: Joint angle from a goniometer] – used to measure the angle/range of motion in a joint. | With usual therapy including therapist communication
Urinary incontinence (women) ^51^ | EMG, vaginal and/or anal squeeze pressure, ultrasound | With pelvic floor muscle training
Urinary incontinence after prostatectomy^50^ | Biofeedback-assisted pelvic floor muscle training – trains the patient to strengthen and control the muscle in the pelvic floor (eg, muscles involved in maintaining continence) and to recognize when they are using the wrong muscles. Recordings of muscle tension from sensors on the abdomen and in the vaginal canal are shown to the patient so they can learn to recognize and control muscles tension. | Varied - electrical stimulation

Abbreviations: BVM = blood volume monitoring, BVP=blood volume pulse, EEG = Electroencephalograph, EMG = electromyograph, IMU = inertial measurement units, GSR = galvanic skin response, LENS = low-intensity neurofeedback system, PMR = progressive muscle relaxation, SMR = sensorimotor rhythm, TEMP = peripheral temperature feedback.

Figure 4 Map of the evidence from systematic reviews of biofeedback interventions by clinical condition, evidence of effectiveness, and level of confidence

## KEY QUESTION 3 In which populations has hypnosis been examined, and what is the evidence of effectiveness and harms in each of these populations?

### Summary of Findings

We identified 14 systematic reviews examining the effectiveness of hypnosis on a wide range of clinical conditions. We found low-confidence evidence that hypnosis is effective for weight loss in obese adults,^40^ for reducing anxiety in patients with cancer,^18^ and for symptoms experienced during breast cancer treatment.^24^ We identified low-confidence evidence that hypnosis provides no benefit for smoking cessation^48^ or schizophrenia.^47^ No effects on secondary and/or global outcomes were observed for labor and childbirth,^38^ or IBS,^35^ though the confidence in these findings was low.

### Detailed Findings

We identified 14 systematic reviews examining the effectiveness of hypnosis on primary/diagnosis-related outcomes, secondary outcomes, and global outcomes such as quality of life. Hypnosis was generally administered by a professional, and in some cases the intervention also included a self-hypnosis component. For a few conditions, the effectiveness of self-hypnosis alone was examined (eg, labor)^38^ The number of controlled trials in the systematic reviews ranged from 1 (postnatal depression)^28^ to 20 (cancer anxiety)^18^ and the number of included participants ranged from 63^28^ to just under 3,000 (Table 3).^38^ Across all reviews, 10 examined only primary diagnosis-related outcomes, 4 examined secondary outcomes, and 2 examined global outcomes (Table 10 in Appendix D).

Across conditions, the evidence examining the effectiveness of hypnosis for the treatment of primary/diagnosis-related outcomes depended largely on the condition examined (Figure 5). Although our confidence estimates were low due to methodological concerns about the trials included in the SRs, there is evidence that hypnosis provides benefit over comparator interventions for anxiety related to cancer,^18^ breast cancer care (ie, pain, distress, fatigue, nausea/vomiting, and hot flashes),^24^ and for weight loss in obese participants.^40^ Weight loss was significantly greater for those hypnosis interventions that included a self-hypnosis component, and for trials comparing cognitive behavioral therapy (CBT) combined with hypnosis to CBT alone.^40^

Findings from the systematic reviews also suggest with moderate confidence that hypnosis may potentially provide symptom relief and improved overall gastrointestinal functioning for patients with IBS.^35^ However, findings indicate no effect on secondary outcomes for IBS (ie, pain, diarrhea, constipation, and bloating/distension, depression, anxiety), or health-related quality of life.^35^ In addition, while our confidence ratings were low due to methodological limitations, findings also indicate the potential for hypnosis to provide symptom-related relief for anxiety related to generalized anxiety, phobic disorders, test anxiety,^17^ and medical procedures,^19^ as well as insomnia.^34^

We identified limited evidence that hypnosis provides no benefit for smoking cessation,^48^ or for schizophrenia,^47^ nor does it have any effect on a wide range of maternal and infant outcomes during and after labor (Table 10 in Appendix D).^38^ Findings related to all other conditions were insufficient (Figure 5; Table 10 in Appendix D).

Contributing to the generally low confidence levels for diagnosis-related outcomes were small combined samples sizes, poor study quality, and inconsistencies across studies included in the systematic reviews. For secondary and global outcomes, sample sizes were generally lower, results were inconsistent across studies, and study quality was generally poor (Table 7 in Appendix C). Although not a factor considered in our limited method of rating of confidence, comparison groups even within conditions were heterogeneous, ranging from no intervention to a wide range of active interventions.

Figure 5 Map of the evidence from systematic reviews of hypnosis interventions by clinical condition, evidence of effectiveness, and level of confidence