# Methods

## Topic Development

This topic was nominated by Dr. Ben Kligler, National Director of the Coordinating Center for Integrative Health (IHCC) and Laura Krejci, Associate Director of the Office of Patient Centered Care and Cultural Transformation (OPCC&CT). We further developed the scope of the project in collaboration with our operational partners and Technical Expert Panel (TEP). The key questions (KQs) for the evidence map were as follows:

KQ1 In which populations has guided imagery been examined, and what is the evidence of effectiveness and harms in each of these populations?
KQ2 In which populations has biofeedback been examined, and what is the evidence of effectiveness and harms in each of these populations?
KQ3 In which populations has hypnosis been examined, and what is the evidence of effectiveness and harms in each of these populations?

The analytic framework for our approach to the research questions is shown in Figure 1.

Figure 1 Analytic framework

## Search Strategy

The search strategies were developed in consultation with a research librarian, and were peer-reviewed by a second research librarian using the instrument for Peer Review of Search Strategies.^10^ We conducted a review of the literature by systematically searching, reviewing, and analyzing the scientific evidence as it pertained to the research questions. To identify relevant systematic reviews/meta-analyses, we searched Ovid MEDLINE Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Ovid MEDLINE Daily and Ovid MEDLINE, Ovid PsycINFO, CINAHL, Epistomonikos, and Ovid EBM Reviews Cochrane Database of Systematic Reviews (CDSR, DARE, HTA, Cochrane CENTRAL, etc). We searched all available years of publication from database inception (1946 for Ovid MEDLINE®) through March 2018, and performed an update search of Ovid MEDLINE in September 2018. To identify additional reviews, we reviewed the bibliographies of relevant reviews of reviews, searched the review registry PROSPERO for completed reviews, and queried subject matter experts.

## Study Selection

We assessed the titles and abstracts yielded by the literature search based on pre-specified criteria (Appendix B) using Abstrackr,^11^ an online tool for screening citations, and retrieved potentially relevant articles for review at the full-text level. Two investigators independently assessed all abstracts and full-text articles for inclusion, and resolved disagreements through discussion and consensus.

We identified systematic reviews and meta-analyses that included controlled trials of guided imagery, biofeedback, or hypnosis in subjects defined by specific medical conditions or risk groups, such as elderly populations or patients in intensive care. The criteria for population, interventions, comparators, outcomes, timing, and setting (PICOTS) that apply to each key question are specified in Table 1.

Potentially eligible systematic reviews met all of the following quality criteria: 1) clearly reported their search strategy and inclusion criteria; 2) performed a comprehensive search of at least 2 electronic databases; and 3) assessed the methods and potential risk of bias in the included trials using validated criteria.^12^

We included systematic reviews that focused explicitly on the interventions of interest, and excluded systematic reviews that examined guided imagery, biofeedback, or hypnosis as one of multiple interventions for a condition or population. To mitigate potential loss of information by excluding well-conducted reviews with comprehensive scopes that included interventions of interest along with other interventions for distinct health conditions, we compared the findings and included trials from these more broadly scoped reviews with those of systematic reviews that were more narrowly focused on our target interventions.

In the evidence map, each data point – or bubble – represents the evidence for guided imagery, biofeedback, or hypnosis for a distinct health condition. In order to define the health conditions for the evidence map in which target interventions have been studied, we comprehensively listed the health conditions studied across all potentially eligible systematic reviews. Through iterative discussions among the authors and the technical expert panel, we collapsed similar health conditions into a single broadly defined category when clinically appropriate, particularly if a single systematic review included the breadth of the conditions. For example, we combined headache and migraines into a single category and selected a systematic review that covered the wider scope.^13^ However, we did include systematic reviews examining biofeedback for both stroke^14^ and the more broadly defined (including stroke) balance/gait training^15^ because the modalities and findings differed between the reviews. When there were several qualified reviews of an intervention for the same health condition, we selected a single review based on how recent it was and its methods, scope, and applicability.

Table 1 PICOTS by key question

Key Questions | KQ1. In which populations has guided imagery been examined, and what is the evidence of effectiveness and harms in each of these populations? | KQ2. In which populations has biofeedback been examined, and what is the evidence of effectiveness and harms in each of these populations? | KQ3. In which populations has hypnosis been examined, and what is the evidence of effectiveness and harms in each of these populations?
Population | Adults (18+) receiving an intervention of interest for any health condition. Children and adolescents are excluded. Exclude studies of healthy/non-elderly volunteers.
Interventions | Guided imagery (also “guided meditation,” “yoga nidra,” “mental practice,” “mental rehearsal,” “Katathym-imaginative Psychotherapy,” “autogenic training,” and “integrative restoration”). Studies of guided imagery as part of a complex or multicomponent intervention are excluded. | Biofeedback (also “neurofeedback,” and “neurotherapy”). Studies of biofeedback as part of a complex or multicomponent intervention are excluded. | Hypnosis (also “hypnotherapy”). Studies of hypnosis as part of a complex or multicomponent intervention are excluded.
Comparators | Systematic reviews and meta-analyses comparing an intervention of interest to usual care, placebo, or another intervention.
Outcomes | Effect on diagnosis-related symptoms; secondary outcomes (eg, anxiety, depression, or other mental health outcomes that are not primary to the diagnosis; sleep); global health outcomes (eg, quality of life, activities of daily living, mobility, social functioning, employment); and harms.
Timing | Any duration and follow-up.
Study design | Systematic reviews and meta-analyses that include randomized or non-randomized controlled trials. Non-systematic reviews, reviews of reviews, and primary studies are excluded.
Setting | All health care settings.

## Data Abstraction

Data from studies meeting inclusion criteria were abstracted by 1 investigator and confirmed by at least 1 additional reviewer. From each review, we abstracted the following where available: focus of the systematic review (ie, intervention of interest, multiple interventions, condition-specific), number of studies included from the systematic review and total number of subjects included in the review, whether duration was provided, condition treated, and summaries of relevant findings (ie, condition-related symptoms, harms, cost).

We abstracted outcomes data in 4 categories: diagnosis-related outcomes, secondary outcomes, global health outcomes, and harms (Figure 2). We defined diagnosis-related outcomes as symptom outcomes that were directly related to the target health condition; for example, pain in headache. Global health outcomes were those that extended beyond a single symptom, and included outcomes such as quality of life and functional status. Secondary outcomes included sleep, anxiety, depression, or other outcomes that are not primary to the diagnosis. We also examined harms outcomes, but these were almost always poorly reported and thus are not represented in the evidence maps.

## Quality Assessment

To qualify for inclusion in our evidence map, systematic reviews had to have assessed the methodological quality of clinical trials using a standardized instrument. These primary adjudications were taken at face value and used to rate the overall body of evidence.

## Data Synthesis

We used the vector graphics in Microsoft Excel (2016) to generate scatter plots based on categorical values representing levels of effect and confidence in the evidence. Each bubble in the scatter plots represents the summary of findings for 1 of 3 outcome categories (diagnosis-related, secondary, and global), based on data from trials reported in the systematic reviews. We also provide a brief narrative synthesis of the findings.

We classified the effect of the intervention for each targeted health condition and outcome as follows:

1) No effect: a preponderance of null or negative findings.
2) Unclear: the systematic review reported mixed findings for a single outcome with no preponderance of either benefit or negative effects; or the number of studies, sample sizes, and/or the methodological quality of the studies were insufficient to form a conclusion about effectiveness.
3) Potential positive effect: mixed findings that include some evidence of benefit; or multiple outcomes within the same category (diagnosis-related/secondary/global) with at least 1 clear finding of benefit; or mixed findings for a single outcome with a preponderance of evidence of a positive effect.
4) Positive effect: numerous studies or a large sample showing a positive effect.

For a modality to be classified as having a positive effect required consistent, statistically significant effects from well-conducted trials. When there were mixed findings for a single outcome that included both positive and null findings, we classified the overall effect as either unclear or potentially positive, depending on the preponderance of findings and the quality of the evidence. If the findings across a group of studies were truly mixed to the extent that there was no preponderance of evidence in 1 direction or another, or if there were methodological limitations in the included trials, we classified it as unclear/insufficient. However, if there were a clear signal for benefit on at least 1 outcome, we classified the overall body of evidence as having a potential positive effect.

## Rating the Body of Evidence

For each conclusion on the effect of an intervention (ie, no effect, unclear, potential positive, or positive effect) we characterized the level of confidence in the body of evidence specific to that outcome and health condition. We calculated a rough estimate of confidence based on the number of participants in the included trials; the quality of the included trials, and the overall risk of bias; whether there were serious inconsistencies in the findings; and any limitations in the applicability of the evidence (Appendix C). Table 2 outlines the criteria we used for scoring.

Table 2 Domains for assessing level of confidence

Domain; range of points | Description
Sample Size;; 1 to 3 | 1: N≤100; 2: N=100-500; 3: N=500+
Consistency;; −1 or 0 | 0: No major flaw; −1: Serious inconsistency
Directness;; −1 to 0 | 0: No major flaw; −1: Limited applicability
Overall ROB/study quality;; −1 or 0 | 0: Unclear or low ROB (good quality); −1: High ROB (poor quality)

ROB = Risk of bias

We used the sum of points from each domain to classify the level of confidence into 4 categories as follows:

(3) High: Consistent findings from larger studies with low risk of bias.
(2) Moderate: Larger studies that may have limitations in study quality, applicability, or consistency of findings.
(1) Low: Small sample size, or major deficiencies in the body of evidence.
(≤0) Insufficient: No evidence is available, or the body of evidence has unacceptable deficiencies.

For the evidence maps, we grouped together studies with either unclear effect or insufficient level of confidence into a combined category of Unclear/Insufficient evidence.

## Peer Review

A draft version of this report was reviewed by technical experts and key stakeholders. Reviewer comments and our responses are provided in Appendix E.