# Introduction

The Veterans Health Administration (VHA) is currently transforming its healthcare model, with a shift from problem-based disease care to a personalized, proactive, patient-driven (whole health) care model that prioritizes active patient engagement in a patient-centered health care system. Part of this mission is to identify, develop, and implement new practices and approaches that are found to be effective in helping to promote the transformation to a patient-centered model that focuses on the Veterans’ goals and priorities for their health. The VHA established the Integrative Health Coordinating Center (IHCC) with the Office of Patient Centered Care and Cultural Transformation (OPCC&CT) to aid in development and implementation of complementary and integrative health (CIH) strategies across the VHA. Guided imagery, biofeedback, and hypnosis are low-risk complementary treatment modalities that may have the potential to benefit patients experiencing a wide range of conditions, including pain,^1–3^ stroke recovery,^1,4^ hypertension,^5^ and gastrointestinal conditions,^6^ as well as mental health conditions^1^ such as anxiety^7^ and stress.^8^

The purpose of this report is to provide a broad overview of the effectiveness of guided imagery, biofeedback, and hypnosis, and the health conditions for which these interventions have been examined, and to display the overall findings in the form of evidence maps. Evidence maps are a relatively new form of evidence synthesis, and their purpose is to identify research gaps and future research needs, rather than to conduct comprehensive, in-depth analyses and form conclusions about a focused research question. Although standardized definitions and methodology are still being established, they generally include a systematic search of a broad field of research and a visual representation of the body of literature.^9^ The evidence maps will be used to guide and support decision-making about these treatment modalities in the VHA.