# APPENDIX E Peer Reviewer Comments and Author Responses

Rev # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | Yes | Noted, thank you.
2 | Yes | Noted, thank you.
3 | No - unclear how more recent reviews were selected | Thank you. In the Methods section we describe the selection process as follows: when there were several qualified reviews of an intervention for the same health condition, we selected a single review based on its recency, methods, scope, and applicability.
4 | Yes | Noted, thank you.
5 | Yes | Noted, thank you.
6 | Yes | Noted, thank you.
Is there any indication of bias in our synthesis of the evidence?
1 | Yes - Well bias is too strong a word--I would say no bias at all in the synthesis but some bias or at least excessive caution in how the results are presented in the narrative. Much more detail in my comments on this below. | Thank you. We have responded in the comments below.
2 | Yes - (1) Should have included heart rate variability biofeedback (HRVB) in review of biofeedback. (2) As a result of (1), medical conditions and target populations listed in Table 3, page 23 that are responsive to HRVB were not found on Table 4, page 30 (e.g. Anxiety, Depression, IBS, Insomnia, muscular-skeletal Pain, PTSD to name a few). I believe that even if the findings of the literature search of HRVB showed No effect and Level of Confidence Unclear/Insufficient evidence, this would have been reported if HRVB had been considered at all. | Thank you. Heartrate variability biofeedback was captured by our search, however there was only 1 systematic review, and it did not meet inclusion criteria. We added a sentence to the Methods section of the paper noting the absence of this modality. We acknowledge limitations of the evidence map methodology – we have added more language about these limitations to the report and executive summary.
3 | Yes - 1. There is a major concern in regard to the criticism that more blinded trials are needed. While blinding is critically important in drug trials, blinding in behavioral trials is often impossible and frequently ill-advised. Consider that blinding in drug trials is employed to control for the effects of expectancy on outcomes, as the mechanism of change is hypothesized to be the chemical action of the drug. In behavioral trials, mechanisms are psychological. In the case of hypnosis specifically, expectancy change is explicitly a mechanism of change (among others), which has been supported in the research literature. To blind patients to hypnosis would be to impair the mechanism of change, and thereby decrease efficacy. Also, how would be patients be blinded? Would the investigator not use the word “hypnosis” in the consent document (which could be considered unethical if the researcher really considered the intervention to be hypnosis)? Would the investigator not use the word “hypnosis” during the intervention? In that case, the trial would not be testing hypnosis, if would be testing some other intervention. Research indicates that when you do not label the intervention hypnosis, effect sizes decrease, again, biasing against the hypnosis intervention. Meta-analyses and reviews which include “hypnosis” interventions which do not use the term are therefore potentially biased against the efficacy of intervention. There is concern that such criticism about blinding is simply echoing conclusions drawn from previous, less than thoughtful, reviews. This review has an opportunity to be both more thoughtful and educated on the topic. To the extent that other behavioral interventions incorporate expectancy as a mechanism of change, these criticisms apply. | Thank you for bringing up this point. We have revised the paragraph in question (in Discussion) to reflect both sides of the debate in regard to blinding in CAM trials.
4 | Yes - Some studies have been overlooked; and by only using reviews, other valuable findings have been excluded. Additionally, myriad studies combine guided imagery with another method, or define the intervention as a combination, so we miss out on some good evidence.; For instance, a lot of guided imagery begins with simple relaxation – it’s part of the guided imagery process. This is sometimes described by the authors as ‘relaxation plus guided imagery’, and I fear those studies may have been excluded. | Thank you. This will depend on how each systematic review defined guided imagery and chose to include/exclude studies. Systematic reviews that did not individually analyze the results by intervention were excluded unless the intervention was guided imagery combined with another modality and the comparator was guided imagery alone. We acknowledge the limitations of evidence mapping, including the potential to miss some good evidence given our reliance on systematic reviews and we have added more language about these limitations to the report and executive summary.
4 | One study which, under the criteria, would have been excluded, would be the Guarneri study out of Scripps, published in Military Medicine a few years ago, where the intervention was a combination of guided imagery and Healing Touch, two distinct techniques.; Nonetheless, the study was strong and yielded exciting data: it had an ‘n’ of 123 Camp Pendleton Marines, between deployment, with moderate to severe symptoms of PTSD. As compared with standard care (which included individual psychotherapy, medication and EMDR,) these subjects showed robust improvement on several key symptoms, in the short span of 3 weeks (6 sessions).; Given the fact that this was a military population in an RCT with a respectable number of subjects, who had unusual gains in a famously refractory condition, I think this combo is worth a mention, even as a footnote. If what we are after is practical solutions that work in real time, (and I know we all are,) isn’t this combo exactly what we want to know about, and test further with our vets? | Thank you. Individual RCTs would not have been captured in this paper given that we were searching for systematic reviews.
5 | No | Noted, thank you.
6 | No | Noted, thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
1 | No | Noted, thank you.
2 | Yes - Numerous articles reporting on effects of HRVB. I suggest re-doing the entire Biofeedback section using a literature search with keywords “HRV biofeedback’. Relatedly, for some unknown the searches for ‘neurofeedback’ and ‘neurotherapy’ did not yield the findings I would have expected it to report. Furthermore, I recommend pulling Biofeedback out of ESP reporting as it is presently combined with Guided Imagery and Hypnosis and doing a separate report with Biofeedback alone. | Thank you. Search terms for heartrate variability biofeedback, neurofeedback, and neurotherapy were included in our search. One systematic review on HRV occurred in the literature yield but did not meet inclusion criteria. Though citations on neurotherapy occurred in the search yield, there were no systematic reviews that meet inclusion criteria. The search for neurofeedback yielded a number of citations, and the SRs included in the evidence map include this modality (see Table 4); The reason why guided imagery and hypnosis are combined with biofeedback in this report is because a requested was made by the operational partners at the VA for evidence maps of the three interventions in a single report.
3 | No | Noted, thank you.
4 | Yes - Yes, I believe so. See attached document for additional systematic reviews, as well as recent or notable individual studies.; One area that may have been partially overlooked regards medical procedures, such as dialysis, ventilator weaning, needle sticks, chemo, radiation tx, general surgery, etc. Even where there are too few studies to generate a review, the findings – on ventilator weaning, for instance – are impressive.; Benefits of imagery for post-op pain, blood loss, opioid and analgesic use, length of stay, bowel motility, pre- and post-op anxiety are also worth including – there’s a lot. I have included several in my attached document.; There are studies of guided imagery up-regulating immune function (not necessarily related to cancer – also re flus, colds, herpes, etc) that perhaps belong here as well.; I also think there are significant benefits for enhancing performance, focus, mastery of tasks, physical competence in sport or rehab, that have important implications for our vets with neurodegenerative disease, injuries, stroke, TBI, limb loss, and severe anxiety.; I’ve also included studies on smoking cessation and several unpublished papers and a chapter on imagery and PTSD.; I just want to encourage you all to give guided imagery a second, more exhaustive (and perhaps exhausting!) look.:-) | Thank you for the list. As stated previously, primary studies would not have been captured by the evidence map format. The suggested systematic reviews you noted were captured by our search but did not meet our inclusion criteria. We acknowledge the limitations of evidence mapping, including the potential to miss some good evidence given our reliance on systematic reviews, and we have added more language about these limitations to the report and executive summary.
4 | ADDED AFTER PEER REVIEW BY EMAIL:; This is a big P.S., discovered late, for which I apologize, but of some consequence to the committee’s inquiry:; I’ve begun working on a paper I’m giving later on in the year on the primal importance of guided imagery for managing separation anxiety, learned by humans from baby- and toddler-hood, across all cultures, and how it’s a built-in coping tool of great consequence to adults, especially regarding grief, trauma and any deep distress.; It meant going through the psychodynamic attachment literature, something I haven’t done in a while. And lo and behold, I found a major term for guided imagery I’d never run into, called attachment security priming. It talks about an element I’ve always inserted as the central healing element in the imagery I construct, so shame on me for not knowing the term. We are all in our silo’s!!; It turns out that security priming studies are all over the place, and it primarily consists of guided imagery that creates a sense of security similar to that induced by the presence of supportive others who provide love, comfort and security, termed ‘attachment figures’. (Occasionally it’s simple exposure to words, such as love, hug, affection, either subliminally or supra-liminally. Sometimes it’s exposure to pictures showing these things. But 80% of recent studies ask participants to imagine such scenarios or relationships, or recall memories of experiencing being loved by such attachment figures – which is defined as guided imagery or visualization.); The studies using guided imagery yield the most powerful outcomes, in terms of improvements in mood, attitude toward new situations, death anxiety, aggression, compassion and depression.; I discovered this in a literature review of security priming studies from the last 2 years, (106 articles), Attachment security priming: a systematic review by Omri Gillath and Gery Karantzas, part of a themed issue on Attachment in Adulthood, edited by Jeffry A Simpson and Gery Karantzas in Current Opinion in Psychology 2019, 25:86-95. See www.sciencedirect.com/.; Anyway, late as it is, I felt it important to alert you to this newly discovered treasure trove of guided imagery studies. Hope you can include them in your inquiry. It gives guided imagery its due. I can’t read enough of these articles, myself. | Thank you for these suggestions. We examined the systematic review on attachment security priming, but determined it was not eligible for inclusion on the evidence map because the studies were conducted in healthy volunteer samples rather than targeting a specific health condition.
5 | Yes - Van Doren, et al 2018, European Child & Adolescent Psychiatry | Thank you. This systematic review did not meet our inclusion criteria because the studies were in children, and we were specifically searching for adult populations.
6 | No | Notes, thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
1 | I have one major concern which runs throughout the document regarding the order in which conclusions are stated and summarized and what that communicates or does not communicate to the reader. Happy to discuss further. Overall I think the science here is excellent but I find the presentation of the results overly cautious with some potential to reinforce existing biases regarding these therapies. | Noted. Responses below.
1 | P3 Line 13. I would list the positive finding regarding arthritis first and then the statement about the findings being mixed and the confidence low second. Clinicians will be reading looking for “where does it really work.” If we bury this important info behind a statement which says “we don’t know if it really works for most things” rather than highlight the ones with moderate confidence of positive effect this will be less helpful to clinicians as they are more likely to stop paying attention after that first sentence stating the mixed findings and low confidence. I feel the paper needs to be edited throughout with this principle in mind: highlight the positive findings first, followed by the mixed, uncertain, negative findings. This is not just for political reasons BTW but really from my experience as a clinician using this type of document.; Line 22. Same comment here—would state the important finding re biofeedback and HA first, then the “overall findings for most conditions were insufficient.”; P5 line 40. Summary omits positive findings on IBS and hypnosis.; P18line 10. As above should state positive findings first in the summary section; P21 line 13 As above would switch the order here and state positive conclusions first.especially given the clear statement you are making about biofeedback and HA. Why undermine the potential meaning and impact of the positive finding by prefacing it with the negative findings?; Line 33-36. Same comment, would switch the order here.; P25 line 19. Seems misleading re IBS findings—which were positive for overall symptoms and GI function although negative for other outcomes. Again leaving that out is confusing and inconsistent with what is stated on line 47 and portrayed in the summary figure on p 27 | Thank you. We have edited the document throughout to state the positive findings first in each section, as suggested.
1 | line 37: this paragraph omits the fact that hypnosis was found to be effective with moderate confidence for symptom relief and improved GI functioning in IBS (see page 32 line 47). To omit this and then only state that “nor is hypnosis effective for secondary or global outcomes in patients with fibromyalgia or irritable bowel syndrome”; This omission is repeated in multiple spots in the paper. Also the summary table in this section is misleading re IBS—and not consistent with table in the detailed section | Thank you. Only findings of positive effect were summarized in the text cited; because there was moderate-confidence evidence of potential positive effect for IBS, those results are not represented. The figure showing the summary of findings across all 3 interventions likewise displays only the findings of positive or null effect, and excludes potential positive and unclear effects.
1 | Line39. Why include the statement “None of the available evidence…reached a high level of confidence’? Very often guidelines even have no highest level evidence (see ACP guidelines on back pain from last year). I think this statement can prejudice the reader especially readers who do not understand that the level of confidence in the evidence has to do with the quality of the studies to date not with the likelihood of the conclusions being right or wrong. | Thank you. As suggested, we have removed this statement.
1 | P19line 10 Would add “With the exception of arthritis/rheumatic diseases” otherwise this is very incongruous when you look at the summary table on the following page where there is a moderate bubble on evidence of positive effect for these conditions. | Thank you. We have made the suggested change to the text.
1 | Line51-56. Why are these findings not included in the summary? These conditions are very common and of great relevance to clinicians. You include other low-confidence conclusions in the summary why omit these findings?; P 28 line 50. The findings re IBS symptoms and GI function should be included here as well.; P 29. Summary figure omits IBS findings, again not consistent with the summary figure in the detailed section on p 27; Line 50. IBS omitted in the conclusions paragraph. | Thank you. The purpose of the summary graph is to show clearly positive or clearly null effects, even if the level of confidence in the evidence was low. We have not included less clear or mixed findings (potential positive or unclear effects).; The findings on IBS symptoms and GI function were potential positive effects, and were therefore not included on the summary graph (Figure 6).
1 | P 30 Lines 8-14. Question the need to include as this seems editorial and somewhat prejudicial. Des the article cited specifically refer to the issue of non-blinding in CAM studies or in the literature overall? The statement here makes it seem as if this is unique to CAM studies. Also the statement beginning “It is therefore not clear” also seems somewhat prejudicial to me and possibly unnecessary. | Thank you. We have accounted for your feedback by framing this as a debate representing both sides regarding the need for blinding in CAM studies rather than taking a position.
1 | Line 43 I do not think it is correct that all of the findings here are not clinically actionable. Biofeedback for HA, guided imagery for RA, etc—particularly given the huge safety margin for these approaches compared to many pharmaceuticals I think they are actionable. If you need to include this statement please clarify with something like “only a few of” or “not all of” these findings. In the clinical standard of care in this area, the safety margin plays a huge role and somewhat counterbalances in many cases the weakness of the published evidence. | Thank you. We have removed the wording that suggests that potential benefits are not clinically actionable.
2 | It appears to be that case that the reviewers lacked background knowledge of Biofeedback methods and findings necessary to do the review successfully. If this is true, could reviewers with the necessary background be recruited to start all over and do the review again and separate from Guided Imagery and Hypnosis? | Thank you. We consult technical experts in the framing of our protocol and search strategy. The format of this review as an evidence map requires high-level synthesis of the subject matter, and as such does not reach the level of granularity of a traditional systematic review.
3 | 2. There is an opportunity to rate the strength of the reviews included. Taking them as equal and at face value misses an opportunity to further comment on confidence. For example, methodological quality may have been rated by those reviews, but was the system for rating quality appropriate? This goes back to the ‘garbage in garbage out’ criticism of reviews in general which could be avoided here and strengthen confidence in overall conclusions. | Thank you. We used the AMSTAR 2007 criteria as a guide and set minimum quality criteria for inclusion. While the AMSTAR 2007 identifies important criteria, there is not one widely agreed upon, validated method for ranking quality beyond that. For example, AMSTAR doesn’t specify which quality assessment methods should be used.
3 | 3. How many of the separate reviews included the same studies? | Thank you. While we originally included multiple competing reviews, we ultimately chose 1 review to represent each condition/bubble, and examined the overlapping studies when there were multiple reviews per condition to make sure there was adequate representation by the selected SR.
3 | 4. Is there an effect of number of studies or number of reviews on confidence? | Thank you. Not directly, but rather indirectly via sample sizes.
4 | At the beginning when you list the TEP, you say I’m from Boston. I was born there but we’re based in Cleveland, Ohio. | Pardon our error on your location. That has been corrected.
4 | Also, as I was finding articles, I realized that another kind of imagery that fits as a search word here is “Guided Imagery & Music” or GIM (Bonny Method) and it completely escaped me. | Thank you. GIM was capture in our search, and 1 systematic review was found, but did not meet inclusion criteria.
4 | Additionally, the term “imagery rescripting” belongs here, particularly for PTSD; and in the treatment of nightmares.; Of course, imagery is often a central, ‘active ingredient’ of a CBT or exposure protocol, but it gets conflated with the other components of treatment, and gets called by another name. So guided imagery doesn’t always get its due! :-(Did my best to make up for that here. :-) | Thank you. Imagery rescripting was captured in our search, and 1 meta-analysis was found, but did not meet our inclusion criteria.
5 | A weakness of the study, that the authors lightly addressed in the summary section, is the limited list medical conditions evaluated for which the 3 treatment modalities are often applied. For example, biofeedback modalities applied to conditions is variable. For ADHD, there is research using both HRV biofeedback and EEG biofeedback (aka neurofeedback) – both have good support and meta-analysis publications (see Van Doren, et al 2018, European Child & Adolescent Psychiatry). Mention of this omission limitation is suggested.; In reference to Table 3, perhaps it could be noted that the absence of a correlation between the treatment modality (GI, Bio, Hyp) and the condition (anxiety, etc) may not reflect absence of evidence because the published studies associated with that condition (e.g., PTSD and biofeedback; PTSD and guided imagery; Insomnia and biofeedback) were not selected or included in the analysis. As this point relates to biofeedback, insertion of this sort of statement might well fit on page 28 at line 12-13.; An alternative would be to make this “absence of evidence” point in the summary at page 35 line 16 so that it covers all 3 treatment modalities (GI, Bio, Hyp). I see the light coverage of this point on page 35 line 32-33, I just think it is important to make this point strongly as some will review the paper and jump to false conclusions that one of the 3 modalities is not effective for a particular condition. | Thank you. As suggested, we have added a statement at the beginning of the Results section explaining that the list of health conditions in Table 3 and the evidence maps is not exhaustive, and that additional evidence may be available for other health conditions but they did not meet our inclusion criteria. We acknowledge the limitations of evidence mapping, including the potential to miss some good evidence given our reliance on systematic reviews and we have added more language about these limitations to the report and executive summary.
6 | 1. The authors clearly spent a lot of time and effort on this, but there is a fundamental error that renders the results to have limited usefulness. The authors failed to break down the various forms of biofeedback in the report. There are references to specific forms of biofeedback and the efficacy of same but the conclusions typically only use the term “biofeedback”. There are many forms of biofeedback including galvanic skin response, surface electromyography, heart rate variability, temperature and neurofeedback. One cannot only use the term “biofeedback” and that is exactly what the authors have done. For example, one could state “There is evidence for the efficacy of heart rate variability biofeedback in the treatment of generalized anxiety disorder”. One should not state “There is evidence for the efficacy of biofeedback in the treatment…”. The field of biofeedback is too diverse to not specifically identify the kind (modality) of biofeedback used.; Page 21 contains the following paragraph:; “Across conditions, the majority of systematic reviews provided insufficient evidence to form conclusions about the effectiveness of different biofeedback modalities on diagnosis-related, secondary, or global outcomes. We found strong evidence that biofeedback is effective for reducing the frequency, duration, and intensity of migraine and tension-type headaches, moderate confidence evidence of benefit on secondary outcomes of headaches such as medication intake, muscle tension, anxiety, and depression, and limited evidence supporting the benefit of biofeedback for self-efficacy.13 We also found strong evidence that biofeedback as an adjunct to PFMT can result in both immediate and long term improvement in urinary incontinence for men after a prostatectomy as compared to PFMT alone, and that the addition of biofeedback had a positive effect on quality of life (moderate confidence).50 There is (moderate confidence) evidence that the addition of biofeedback to usual therapy is more effective for short-term lower limb activity improvement after stroke, such as standing and walking, than usual therapy alone14 and that electrical stimulation with biofeedback is more effective than electrical stimulation alone for fecal incontinence (Figure 4; Table 9 in Appendix D).”; What KINDS of biofeedback apply to the above paragraph? If one was interested in gait training for example, what kind of biofeedback has the found potential of positive effect? | Thank you. In Table 4 we list the various forms of biofeedback that were included on the evidence maps, as described by the representative systematic reviews.; Because this is an evidence map providing a high-altitude view of the topic, a greater level of detail and granularity is unfortunately not possible. We have added some text to the limitations section addressing this point.
6 | 2. There are no definitions provided for the kinds of biofeedback used. What is contingent electrical stimulation? Balloon sensory biofeedback? Indirect biofeedback? External laryngeal manometry? and others. | Thank you. We have added definitions to Table 4, as suggested.
6 | 3. The detailed findings contains the following paragraph:; “We also identified limited (low confidence) evidence that biofeedback hemodialysis has the potential to result in lower rates of mortality and intradialytic hypotension (IDH) in patients undergoing hemodialysis experiencing chronic fluid overload or symptomatic IDH.33 Additionally, in patients with fibromyalgia, electromyograph (EMG), but not electroencephalograph (EEG) biofeedback has the potential to improve short and long term pain (but not quality of life or secondary outcomes).31 Finally, wearable sensors may provide better static steady state balance and health related quality of life outcomes for patients undergoing balance or gait training (Figure 4; Table 9 in Appendix D)”.; This is what the authors should have done throughout the document. As it is we are left with the conclusion on figure 4 which offers no information as to the type of biofeedback that was used for a given disorder. | Thank you. Figure 4 reports the modality as described by the systematic reviews.