# APPENDIX D Findings of Included Systematic Reviews

Table 8 Effects of guided imagery by medical condition and outcome category

Medical condition/target population N controlled trials (N combined participants) | Outcome category | Findings | Summary of effect | Overall confidence
Anxiety^16^; 2 trials (N=44) | Diagnosis-related | [underlined: Anxiety reduction (2 studies, N=44):] Significant reduction within both T and C groups; between group significance NR | Unclear | Insufficient
Anxiety^16^; 2 trials (N=44) | Secondary | [underlined: Frequency of panic attacks (1 study, N=27):] No significant decrease; [underlined: Psychovegetative complaints (1 study, N=27):] Significant reduction within both T and C groups; between group significance NR | Unclear | Insufficient
Anxiety^16^; 2 trials (N=44) | Global | --- | --- | ---
Arthritis/rheumatic disease^20^; 7 trials (N=207) | Diagnosis-related | [underlined: Pain (2 studies, N=208):] Significant reductions reported in all 5 studies. Qualitatively described only, no numeric effect sizes. | Positive | Moderate
Arthritis/rheumatic disease^20^; 7 trials (N=207) | Secondary | [underlined: Anxiety reduction (1 study, N=58):] Significant reduction | Potential positive | Low
Arthritis/rheumatic disease^20^; 7 trials (N=207) | Global | [underlined: QOL (1 study, N=28):] Significant increases in health-related QOL at week 12. Qualitatively described only, no numeric effect sizes.; [underlined: Mobility (2 studies, N=58):] Significant improvements in mobility. Qualitatively described only, no numeric effect sizes. | Potential positive | Low
Cancer^23^; 4 trials (N=199) | Diagnosis-related | [underlined: Nausea/vomiting (2 studies, N=90):] No effect.; [underlined: Comfort/Experience during radiation/chemo (3 studies, N=143):] Significant improvement in comfort (P<0.05); Significantly more positive chemo experience (P<.0001) | Potential positive | Low
Cancer^23^; 4 trials (N=199) | Secondary | [underlined: Anxiety/depression (2 studies, N=116):] significant benefit | Positive | Low
Cancer^23^; 4 trials (N=199) | Global | [underlined: QOL] (1 study, N=56) significant benefit (P<0.01) | Unclear | Insufficient
Cardiac surgery^25^; 6 trials (N=433) | Diagnosis-related | [underlined: Pain (5 studies, N=355):] Significant reduction found in 3 of 5 studies. Mixed findings overall.; [underlined: LOS (4 studies, N=304):] Significant reduction found in 2 of 4 studies. Mixed findings overall. | Potential positive | Low
Cardiac surgery^25^; 6 trials (N=433) | Secondary | [underlined: Anxiety reduction during pre- and post-op (5 studies):] Significant reduction (P<0.05); [underlined: Feeling of calm (1 study, N=25):] significant benefit (P<.01).; [underlined: Fatigue (2 studies):] reduced; [underlined: Sleep (2 studies):] enhanced; [underlined: Anxiety/tension (6 studies, N=433):] Significant benefit in 4 of 6 studies. | Potential positive | Low
Cardiac surgery^25^; 6 trials (N=433) | Global | --- | --- | ---
Critical illness/ICU^27^; 10 trials (N=1363) | Diagnosis-related | [underlined: Pain (6 studies, N=413):] Significant reduction in 3 studies; non-significant reduction in 2 studies; no change in 1 study.; [underlined: Anxiety/tension (8 studies, N=1258):] Significant reduction in 5 studies; non-significant reduction in 3 studies; [underlined: LOS (5 studies, N=1073):] Significant reduction in 3 studies; non-significant reduction in 1 study; no change in 1 study; [underlined: Use of pain meds (2 studies, N=132):] nonsignificant decrease; [underlined: Complications (N=156, 2 studies):] no difference | Potential positive | Low
Critical illness/ICU^27^; 10 trials (N=1363) | Secondary | Non-significant reductions reported in depression, anger, fatigue, morbidity, pain medication; nonsignificant improvements seen in sleep quality, calm (N=814 for calm; N >100 for sleep, N <100 for depression, anger, morbidity). No change in depression, anger, in 1 study each.; [underlined: Patient satisfaction (3 studies, N=941):] nonsignificant increase in 2 studies; no change in 1 study.; [underlined: Cost (2 studies, N=841):] significant decrease in 1 study; no change in 1 study. | No effect | Low
Critical illness/ICU^27^; 10 trials (N=1363) | Global | --- | --- | ---
Fibromyalgia^3^; 4 trials (N=240) | Diagnosis-related | [underlined: Pain (4 studies, N=224):] 50%≤pain relief not significant: RD=0.05 (95% CI: −0.02 to 0.12), P=0.13; 30%≤pain relief favors GI: RD=0.15 (95% CI: 0.01 to 0.30), P=0.04; [underlined: Mean pain intensity (4 studies, N=224):] No difference: SMD=−0.55 (95% CI: −1.27 to 0.16), P=0.13; Only 1 of the 4 studies found significant benefit | No effect | Low
Fibromyalgia^3^; 4 trials (N=240) | Secondary | [underlined: Psychological distress (2 studies, N=119):] significantly favors GI: SMD=−0.49 (95% CI:−0.87 to −0.11), P=0.01. Heterogeneity was not significant: P=0.30; [underlined: Acceptability (4 studies, N=232):] Null effect: 0.01, (95% CI: −0.04 to 0.06), P=0.59. Heterogeneity not significant: p=0.42; [underlined: Coping with pain (3 studies, N=169):] Significantly favors GI: SMD=−0.39 (95% CI: - 0.74 to −0.04), P=0.03. Heterogeneity not significant: P=0.27; Fatigue (1 study, N=64): Reduction not significant: SMD=−0.44 (95% CI: −0.94 to 0.06), P=0.08.; [underlined: Sleep problems:] no data | Potential positive | Low
Fibromyalgia^3^; 4 trials (N=240) | Global | [underlined: 20%≤improvement of health-related QOL (2 studies, N=105):] No effect: RD=0.09 (95% CI: −0.28 to 0.47), P=0.63. Heterogeneity P=0.04; [underlined: Mean health-related QOL (2 studies, N=105):] Not significant SMD=−0.28 (95% CI: 1.04 to 0.49), P=0.48. Heterogeneity P=0.06.; One study (N=40) found marginally significant benefit w/ GI on QOL in both analyses; the other study found no benefit.; [underlined: Disability (1 study):] No effect: SMD=−0.25 (95% CI: −0.74 to 0.24), P=0.32 | Unclear | Insufficient
Headache^42^; 7 trials (N=400) | Diagnosis-related | [underlined: Pain (N=400):] Unclear effect in 3 studies (NR whether there was significant change from baseline), N=63. Significant improvement from baseline in 4 studies (N=337), but in these studies the effect of GI was equivalent to Hypnosis, and inferior to biofeedback. | Unclear | Insufficient
Headache^42^; 7 trials (N=400) | Secondary | --- | --- | ---
Headache^42^; 7 trials (N=400) | Global | --- | --- | ---
Insomnia^34^; 6 trials (N=284) | Diagnosis-related | [underlined: Sleep improvement:] Mixed findings; [underlined: From MA (N ranging from 17 to 53 per analysis):] No significant difference on most indicators (N awakenings during sleep; total sleep time; feeling refreshed in the morning; quality of sleep). Significant improvement on sleep onset latency in 1 study; [underlined: Sleep improvement within-group difference] (5 studies, N=284): 3 studies found autogenic or guided hypnosis-like imagery training produced significant improvement in sleep from baseline to posttreatment. 2 studies found no significant improvement in any of the outcome measures. | Unclear | Insufficient
Insomnia^34^; 6 trials (N=284) | Secondary | --- | --- | ---
Insomnia^34^; 6 trials (N=284) | Global | --- | --- | ---
Menstrual disorders^39^; 2 trials (N=250) | Diagnosis-related | [underlined: Anxiety and depression:] significant reduction (P<0.05) | Potential positive | Low
Menstrual disorders^39^; 2 trials (N=250) | Secondary | --- | --- | ---
Menstrual disorders^39^; 2 trials (N=250) | Global | --- | --- | ---
Musculoskeletal pain^43^; 9 trials (N=325) | Diagnosis-related | [underlined: Pain (9 RCTs, N=325)]: Significant benefit reported in 6 studies; nonsignificant benefit in 2 studies; no difference in 1 study. | Unclear | Insufficient
Musculoskeletal pain^43^; 9 trials (N=325) | Secondary | --- | --- | ---
Musculoskeletal pain^43^; 9 trials (N=325) | Global | --- | --- | ---
Parkinson’s^44^; 2 trials (N=60) | Diagnosis-related | [underlined: Mobility (2 studies, N=60):] Positive results on TUG test significant in only 1 study.; [underlined: Balance (1 study, N=23):] no difference.; [underlined: UPDRS (1 study, N=23):] More benefit in MI group, especially in the mental section; [underlined: Cognitive measure (clock drawing, stroop) in 1 study (N=23):] No difference pre-post | Potential positive | Low
Parkinson’s^44^; 2 trials (N=60) | Secondary | --- | --- | ---
Parkinson’s^44^; 2 trials (N=60) | Global | --- | --- | ---
Stroke^49^; 17 trials (N=735) | Diagnosis-related | [underlined: Balance (11 RCTs, N=430):] SMD=0.81, 95% CI: [0.03 to 1.65], P=0.06, heterogeneity P<0.0001; [underlined: Gait/walking ability (9 RCTs, N=389):] SMD=0.69 [95% CI 0.38 to 1.00], P<0.00001; heterogeneity P=.04; [underlined: Motor function of lower extremities (6 RCTs, N=307):] SMD=0.84 [95% CI 0.45 to 1.22], P<0.0001; heterogeneity P=0.03. | Potential positive | Low
Stroke^49^; 17 trials (N=735) | Secondary | --- | --- | ---
Stroke^49^; 17 trials (N=735) | Global | --- | --- | ---

Abbreviations: CI = confidence interval; GI = guided imagery; ICU = intensive care unit; LOS = length of stay; MA = meta-analysis; MI = motor imagery; NR = not reported; UPDRS = Unified Parkinson’s disease rating scale; P=p-value; QOL = quality of life; RCT = randomized controlled trial; RD = risk difference; SMD = standard mean difference; TUG = Timed Up and Go

Table 9 Effects of biofeedback by medical condition and outcome category

Condition/target population N controlled trials (N combined participants) | Outcome category | Findings | Summary of effect | Overall confidence
Balance/Gait training^15^; 8 (N=243)^f^ | Diagnosis-related | [underlined: Static steady-state balance outcomes:]; Mediolateral - eyes open (4 RCTs, N=104): Favors biofeedback (Hedges’ g = 0.82), 95% CI (0.43 to 1.21).; Mediolateral - eyes closed (3 RCTs, N=84): Favors biofeedback (Hedges’ g = 0.57, 95% CI [0.14 to 0.99]).; Anterior-posterior sway - eyes open: Favors biofeedback (Hedges’ g = 0.55, 95% CI [0.01 to 1.10]); Anterior-posterior sway - eyes closed: Favors biofeedback (Hedges’ g = 0.44, 95% CI [0.02 to 0.86]); [underlined: Dynamic Steady-State Balance Measures:]; Habitual gait speed: No effect (Hedges’ g = −0.19, 95% CI [−0.68 to 0.29]). | Potential Positive | Low
Balance/Gait training^15^; 8 (N=243)^f^ | Secondary | Studies which measured muscle strength, range of motion and physical activity did not report additional effects of WS training | Unclear | Insufficient
Balance/Gait training^15^; 8 (N=243)^f^ | Global | [underlined: Health-related quality of life]: favors biofeedback | Potential Positive | Low
Bell’s Palsy^21^; 4 (N=118) | Diagnosis-related | [underlined: Facial symmetry, synkinesis, lip mobility]: favors biofeedback | Unclear | Insufficient
Bell’s Palsy^21^; 4 (N=118) | Secondary | --- | --- | ---
Bell’s Palsy^21^; 4 (N=118) | Global | --- | --- | ---
Chronic idiopathic constipation^26^; 17 (N=931) | Diagnosis-related | [underlined: Symptom management – constipation score, improved, complete spontaneous][underlined: bowel movements per week]: Mixed findings | Unclear | Insufficient
Chronic idiopathic constipation^26^; 17 (N=931) | Secondary | --- | --- | ---
Chronic idiopathic constipation^26^; 17 (N=931) | Global | --- | --- | ---
Dysphagia^29^; 5 (N=141) | Diagnosis-related | [underlined: Swallow function (2 RCTs, N=51)]: No difference (MD=1.10, 95 CI [−1.69 to 3.89]); [underlined: Hyoid displacement (3 RCTs, N=90)]: Favors biofeedback (MD=0.22cm, 95% CI [0.04 to −0.40], P=0.02).; [underlined: Dependency on tube feeding (2 RCTs, N=53)]: No difference (OR=3.19, 95% CI [0.16 to −62.72]). | Unclear | Insufficient
Dysphagia^29^; 5 (N=141) | Secondary | --- | --- | ---
Dysphagia^29^; 5 (N=141) | Global | --- | --- | ---
Fecal incontinence^30^; 12 (N=approx. 350)^g^ | Diagnosis-related | [underlined: Remission rate (6 RCTs): Favors biofeedback] | Positive | Moderate
Fecal incontinence^30^; 12 (N=approx. 350)^g^ | Secondary | --- | --- | ---
Fecal incontinence^30^; 12 (N=approx. 350)^g^ | Global | --- | --- | ---
Fibromyalgia^31^; 7 (N=321} | Diagnosis-related | [underlined: Pain intensity (7 RCTs, N=289)]: Favors biofeedback (g = 0.79, 95% CI [0.22 to1.36], P=0.006). Subgroup analyses revealed that only EMG-BFB and not EEG-BFB significantly reduced pain intensity in comparison to control groups (g = 0.86, 95% CI [0.11–1.62]).; [underlined: Long term pain intensity (2 RCTs, N=86)]: No difference (g = 0.86, 95% CI [−1.25–2.98], P=0.42). | Potential positive | Low
Fibromyalgia^31^; 7 (N=321} | Secondary | [underlined: Sleep problems (2 RCTs, N=87)]: No difference (g = 0.23, 95% CI [−0.20 to 0.65], P=0.29).; [underlined: Depression (4 RCTs, N=181)]: No difference (g = 0.37, 95% CI [−0.44 to 1.18], P=0.37).; [underlined: Long term depression (3 RCTs, N=120)]: No difference (g = 0.8, 95% CI [−0.51 to 2.11], P=0.23).; [underlined: Fatigue (4 RCTs, N=163)]: No difference (g = 0.38, 95% CI [−0.46 to 1.08], P=0.43). | No effect | Low
Fibromyalgia^31^; 7 (N=321} | Global | [underlined: Quality of life (4 RCTs, N=163)]: No difference (g = 0.62, 95% CI [−0.77 to 2.02], P=0.38).; [underlined: Long term quality of life (2 RCTs, N=68)]: No difference (g = 0.252, 95% CI [−2.94 to 7.98], P=0.37). | No effect | Low
Headache^13^; 94 (N=3500+) | Diagnosis-related | [underlined: Migraine reduction – frequency, duration, intensity]: favors biofeedback; [underlined: Tension type headache reduction – frequency, duration, intensity]: favors biofeedback | Positive | High
Headache^13^; 94 (N=3500+) | Secondary | [underlined: Medication intake]: favors biofeedback; [underlined: Muscle tension]: favors biofeedback; [underlined: Depression]: favors biofeedback; [underlined: Anxiety]: favors biofeedback | Positive | Moderate
Headache^13^; 94 (N=3500+) | Global | [underlined: Self-efficacy]: favors biofeedback | Positive | Low
Hypertension^32^; 36 (N=1,660)^c^ | Diagnosis-related | [underlined: Blood pressure]: No benefit vs pharmacotherapy. Favors sham or non-specific behavioral interventions when combined with relaxation.; (Unclear effect compared with behavioral or sham. Confidence level: Insufficient) | No effect | Low
Hypertension^32^; 36 (N=1,660)^c^ | Secondary | -- | --- | ---
Hypertension^32^; 36 (N=1,660)^c^ | Global | --- | --- | ---
Intradialytic hypotension^33^; 8 (N=716)^d^ | Diagnosis-related | [underlined: All-cause mortality (2 RCTs, N=104)]: Two deaths occurred in patients undergoing biofeedback hemodialysis (HD), when compared with 6 deaths among patients undergoing conventional HD. The pooled effect estimate did not rule out a beneficial or harmful effect of biofeedback dialysis (RR=0.37, 95% CI [0.07–2.01]).; [underlined: Intradialytic hypotension (6 RCTs, N=266)]: Favors biofeedback (RR=0.61, 95% CI [0.44–0.86]).; [underlined: Pre-dialysis systolic blood pressure (7 RCTs, N=203)]: No difference (MD = 3 mmHg, 95% CI [−2-7]).; [underlined: Post-dialysis systolic blood pressure (3 RCTs, N=77)]: Favors biofeedback (MD = 7 mmHg (95% CI [5–19], χ^2^ = 10.52, P=0.005). However, statistical heterogeneity may have resulted from different follow-up times and patient characteristics. | Potential positive | Low
Intradialytic hypotension^33^; 8 (N=716)^d^ | Secondary | [underlined: Pre- and post- dialysis sodium levels (3 RCTs, N=NR)]: No difference.; [underlined: Urea clearance (3 RCTs, N=130)]: No difference.; [underlined: Post-dialysis regional wall motion abnormalities (1 RCT, N=10):] Favors biofeedback. | Unclear | Insufficient
Intradialytic hypotension^33^; 8 (N=716)^d^ | Global | [underlined: Quality of Life (3 RCTs, N=140)]: Mixed findings. | Unclear | Insufficient
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Diagnosis-related | [underlined: Pain]: No difference at 3, 6, 9, 12 months.; [underlined: Self-reported knee function]: Favors biofeedback at 3 months (MD=8.6, P=0.04), but not at 6 or 12 months. | Unclear | Insufficient
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Secondary | --- | --- | ---
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Global | --- | --- | ---
Labor/childbirth^37^; 4 (N=186) | Diagnosis-related | [underlined: Rates of assisted vaginal birth:] No difference; [underlined: Caesarean section]: No difference; [underlined: Augmentation of labor]: No difference; [underlined: Use of pharmacotherapy for pain]: No difference | Unclear | Insufficient
| Secondary | --- | --- | ---
| Global | --- | --- | ---
Raynaud’s^46^; 10 (N=531) | Diagnosis-related | [underlined: Symptom frequency/intensity]: Favors biofeedback | Unclear | Insufficient
Raynaud’s^46^; 10 (N=531) | Secondary | --- | --- | ---
Raynaud’s^46^; 10 (N=531) | Global | --- | --- | ---
Sleep bruxism^22^; 6 (N=126)^e^ | Diagnosis-related | [underlined: First night’s change in EMG episodes/hour (3 RCTs, N=65)]: No difference (MD=−5.05, 95% CI [−10.71 to 0.62]).; [underlined: Fifth night’s change in EMG episodes/hour (3 RCTs, N=39)]: Favors biofeedback (MD=−7.18, 95% CI [−12.54 to −1.83]).; [underlined: EMG activity per hour (2 RCTs, N=26)]: Favors biofeedback. | Unclear | Insufficient
Sleep bruxism^22^; 6 (N=126)^e^ | Secondary | [underlined: SB-related EMG activities (1 RCT, N=12)]: Favors biofeedback.; [underlined: Measurement of SB events – episodes and duration (1 RCT, N=24)]: Favors biofeedback.; [underlined: Pain (2 RCTs, N=26)]: No difference.; [underlined: Sleep quality (2 RCTs, N=35)]: No difference. | Unclear | Insufficient
Sleep bruxism^22^; 6 (N=126)^e^ | Global | -- | --- | ---
Stroke^14^; 18 (N=429) | Diagnosis-related | [underlined: Lower limb activities (17 RCTs, N=417)]: Favors biofeedback (SMD=0.50, 95% CI [0.30 to 0.70]). | Positive | Moderate
Stroke^14^; 18 (N=429) | Secondary | --- | --- | ---
Stroke^14^; 18 (N=429) | Global | --- | --- | ---
Urinary incontinence in women^51^; 22 trials (N=1,361 [biofeedback])^b^ | Diagnosis-related | [underlined: Self-reported symptomatic cure or improvement:]; PFMT + BF versus PFMT (9 RCTs, N=604): Favored PFMT + biofeedback to PFMT alone (RR=0.75, 95% CI: 0.66 to 0.86). However, there was significant heterogeneity in PFMT and subgroup analyses found no difference between groups between biofeedback and no biofeedback.; PFMT vs PFMT + feedback + biofeedback – cure vs no cure (1 RCT, N=152): No difference (OR=1.59, 95% CI:0.43 to 5.87); PFMT + BF versus PFMT + feedback (2 RCTs, N=130): No difference | No effect | Low
Urinary incontinence in women^51^; 22 trials (N=1,361 [biofeedback])^b^ | Secondary | [underlined: Number of leakage episodes in 24 hours]:; PFMT vs PFMT + feedback + biofeedback – cure vs no cure (1 RCT, N=152): No difference (Z=1.04, P=0.30).; PFMT + BF versus PFMT + feedback (3 RCTs, N=267): No difference; [underlined: Pelvic floor muscle function:]; PFMT vs PFMT + feedback + biofeedback – repetitions, endurance, perineometry, modified Oxford Scale, number of fast contractions (1 RCT, N=152): Favored PFMT with feedback and BF group vs. PFMT alone.; PFMT + BF versus PFMT + feedback - % of subjects with increase on EMG assessment, ultrasound displacement, pressure perineometry, digital vaginal palpation, endurance (sitting, standing), amplitude EMG (4 RCTs, N=180): Mixed findings.; [underlined: Frequency of micturition]:; PFMT vs PFMT + feedback + biofeedback (1 RCT, N=152): No difference.; PFMT + BF versus PFMT + feedback (1 RCT, N=40): No difference; [underlined: Symptom distress:]; PFMT vs PFMT + feedback + biofeedback (1 RCT, N=152): No difference.; PFMT + BF versus PFMT + feedback (2 RCTs, N=150): No difference; [underlined: Pad changes in 24 hours:]; PFMT vs PFMT + feedback + biofeedback (1 RCT, N=152): No difference.; [underlined: Adherence to treatment:]; PFMT vs PFMT + feedback + biofeedback (1 RCT, N=152): No difference.; [underlined: Patients’ satisfaction with progress or outcome:]; PFMT + BF versus PFMT + feedback (1 RCT, N=107): No difference | Unclear | Insufficient
Urinary incontinence in women^51^; 22 trials (N=1,361 [biofeedback])^b^ | Global | [underlined: General and incontinence specific quality of life:]; PFMT + BF versus PFMT (9 RCTs, N=497): No difference; PFMT + BF versus PFMT + feedback (3 RCTs, N=201): No difference | No effect | Low
Urinary incontinence after prostatectomy^50^; 13 (N=1,108)^a^ | Diagnosis-related | [underlined: Objective measurement of urinary incontinence improvement]: Favors PFMT + biofeedback (immediate-, intermediate-, and long-term) vs pelvic floor muscle training alone (P=0.023, 0.002, and 0.017, respectively).; [underlined: Subjective measurement of urinary incontinence improvement:] Favors PFMT + biofeedback (intermediate-, and long-term) vs pelvic floor muscle training alone (P=0.034 and 0.005, respectively). There were no significant immediate effects (P=0.108). | Positive | High
Urinary incontinence after prostatectomy^50^; 13 (N=1,108)^a^ | Secondary | --- | --- | ---
Urinary incontinence after prostatectomy^50^; 13 (N=1,108)^a^ | Global | [underlined: Quality of life]: Favors PFMT + biofeedback (immediate- and intermediate-term) vs pelvic floor muscle training alone (P=0.003 and 0.11, respectively). There was no effect on long-term urinary incontinence (P=0.080). | Positive | Moderate

a Biofeedback with pelvic floor muscle training with or without electrical stimulation,

b Biofeedback with pelvic floor muscle training (PFMT) with or without feedback,

c Biofeedback alone or as an adjunct vs. pharmacotherapy, sham, or behavioral interventions,

d Biofeedback hemodialysis vs conventional hemodialysis,

e Biofeedback with swallow therapy,

Abbreviations: BF = biofeedback, CI = confidence interval; EMG = electromyograph; g = Hedge’s g; MD = mean difference, NR = not reported; OR = odds ratio; P = p-value; PFMT = pelvic floor muscle training; RCT = randomized control trial; RR = risk ratio; SB = sleep bruxism; SMD = standard mean difference

Table 10 Effects of hypnosis by medical condition and outcome category

Condition/target population; N controlled trials (N combined participants) | Outcome category | Findings | Summary of effect | Overall confidence
Anxiety^17^; 14 (N=653) | Diagnosis-related | [underlined: Generalized anxiety:] mixed results from 3 studies; [underlined: Trauma:] mixed results mostly non-significant from 2 studies; [underlined: Phobic anxiety:] mixed and positive findings from 6 studies; [underlined: Tests:] mixed results from 3 studies | Potential positive | Low
Anxiety^17^; 14 (N=653) | Secondary | --- | --- | ---
Anxiety^17^; 14 (N=653) | Global | --- | --- | ---
Anxiety, cancer^18^; 20 (N=878) | Diagnosis-related | [underlined: Immediate effect on anxiety:] Hedges’ g: 0.70-1.41; P<0.01; [underlined: Sustained effect on anxiety]: Hedges’ g: 0.61-2.77; P<0.01 | Positive | Low
Anxiety, cancer^18^; 20 (N=878) | Secondary | --- | --- | ---
Anxiety, cancer^18^; 20 (N=878) | Global | --- | --- | ---
Anxiety, medical procedures^19^; 10 (N=525 [anxiety]) | Diagnosis-related | [underlined: Anxiety intensity during and after medical procedure (5 studies, N=264):] Significant difference, favors hypnosis (3 studies, N=206); not significant (2 studies, N=58) | Potential positive | Low
Anxiety, medical procedures^19^; 10 (N=525 [anxiety]) | Secondary | --- | --- | ---
Anxiety, medical procedures^19^; 10 (N=525 [anxiety]) | Global | --- | --- | ---
Breast cancer care^24^; 13 (N=1,357) | Diagnosis-related | [underlined: Pain (4 trials):] consistent significant effect (P<0.05); [underlined: Distress (8 trials):] consistent significant effect (P<0.05); [underlined: Fatigue (3 trials):] consistent significant effect (P<0.05); [underlined: Nausea/vomiting (1 trial):] significant effect (P<0.001); [underlined: Hot flashes (2 trials):] consistent significant effect (P<0.05) | Positive | Low
Breast cancer care^24^; 13 (N=1,357) | Secondary | --- | --- | ---
Breast cancer care^24^; 13 (N=1,357) | Global | --- | --- | ---
Fibromyalgia^3^; 5 (N=388) | Diagnosis-related | [underlined: Pain (2 studies of hypnosis, N=75):] pain relief≥50% significant (P=0.04); pain relief≥30% significant (P=0.005); [underlined: Pain (2 studies of CBT + hypnosis, N=95):] pain relief≥50% not significant (P=0.25); pain relief≥30% not significant (P>0.05); [underlined: Disability (2 studies of CBT + hypnosis, N=95):] No difference (P=0.85) | Unclear | Insufficient
Fibromyalgia^3^; 5 (N=388) | Secondary | [underlined: Psychological distress (1 hypnosis study, N=59):] nonsignificant reduction; [underlined: Psychological distress (2 studies of CBT + hypnosis, N=95):] SMD=−0.50 (95% CI:−0.91 to −0.09) significant reduction P=0.02 | Unclear | Insufficient
Fibromyalgia^3^; 5 (N=388) | Global | [underlined: Health-related quality of life at end of treatment (1 hypnosis study, N=59):] Not significant; [underlined: Health-related quality of life at end of treatment (2 studies of CBT + hypnosis, N=95):] improvement≥20% RD=0.18 (95% CI: −0.01 to 0.38) not significant (P=0.07) | Unclear | Insufficient
Insomnia^34^; 6 (N=218) | Diagnosis-related | [underlined: Within group:] Significant improvement in either from baseline to post-treatment (5 studies); [underlined: Between group:] Significantly more effective than comparator (4 studies); No difference (1 study); less effective than comparator (1 study) | Potential positive | Low
Insomnia^34^; 6 (N=218) | Secondary | --- | --- | ---
Insomnia^34^; 6 (N=218) | Global | --- | --- | ---
Irritable bowel syndrome^35^; 8 (N=464) | Diagnosis-related | [underlined: Adequate symptom relief at end of therapy:] Favored treatment: RR=1.69 (95% CI: 1.14-2.51); P=0.009; [underlined: Global gastrointestinal score at end of therapy:] T group experienced greater reduction. SMD=−0.32 (95% CI: −0.56 to −0.08); P=0.008; [underlined: Adequate symptom relief at long-term follow-up (1 study):] Favored treatment. RR, 2.17 (95% CI: 1.22-3.87); P=0.008; [underlined: Global gastrointestinal score at long-term follow-up (2 studies):] No difference. SMD=−0.57 (−1.40 to 0.26); P=0.180 | Potential positive | Moderate
Irritable bowel syndrome^35^; 8 (N=464) | Secondary | [underlined: Pain, diarrhea, constipation, bloating/distention, depression, anxiety:] No difference at end of therapy | No effect | Low
Irritable bowel syndrome^35^; 8 (N=464) | Global | [underlined: Impaired health-related quality of life (N=290):] No difference SMD=−0.56 (95% CI:−1.44 to 0.32); P=0.21 | No effect | Low
Labor/childbirth^38^; 9 (N=2,954) | Diagnosis-related | [underlined: Use of pharmacological pain relief or anesthesia during labor and childbirth (8 studies,][underlined: N=2916):] Average RR=0.73, 95% CI: 0.57 to 0.94; Significantly less likely to use; Z=2.47 (P=0.014); [underlined: Satisfaction with pain relief (2 trials, N=264):] No effect for all except women who had water immersion births (1 trial, N=174) MD=0.52; 95% CI: 0.04 to 1.00; [underlined: Sense of coping in labor (1 trial, N=420):] MD=0.22; 95% CI: −0.14, 0.58. No difference (P=0.22).; [underlined: Spontaneous vaginal birth (6 studies, N=2361):] No difference. Average RR=1.12; 95% CI: 0.96 to 1.32. | Unclear | Insufficient
Labor/childbirth^38^; 9 (N=2,954) | Secondary | [underlined: Pain intensity]: no difference in 2 of 3 trials; [underlined: Satisfaction with childbirth experience] no difference in 2 of 3 trials (trial with significantly higher satisfaction: N=1,126, P=0.0023); [underlined: No significant difference in any of the following (N:~400-2,800):] breastfeeding at discharge; assisted vaginal birth; cesarean section; admission to NICU; Apgar score less than 7 at 5 minutes; use of epidural; preterm birth; length of labor; perineal trauma; induction of labor; augmentation of labor with oxytocin; primary postpartum hemorrhage; cost; need for postpartum blood transfusion; mother or newborn readmission; [underlined: Significant effect in 1 trial each:] postnatal depressive symptoms; number of maternal days in hospital (>2 days after the birth) | No effect | Low
Labor/childbirth^38^; 9 (N=2,954) | Global | --- | --- | ---
Obesity/weight loss^40^; 10 studies/ 14 trials by Tx (N=882) | Diagnosis-related | [underlined: Mean weight loss at post (14 trials, N=882):] MWES=1.58 (SE 0.09; 95% CI 1.40 to 1.76); Significant effect (Z=17.56, P=0.001, two-tailed); [underlined: Mean weight loss at follow-up (6 trials, N=185):] MWES=0.88 (SE=0.18, 95% CI 0.53 to 1.23); Significant effect (Z=4.89, P=0.001, two-tailed); [underlined: Mean weight loss with (7 post trials) vs without (7 post trials) adjunctive self-hypnosis]: Significant effect for both (P≦0.001), but significantly greater effect for interventions including self-hypnosis (Q=19.24, df=1, P≤.001); [underlined: Mean weight loss at follow-up for combined CBT & Hypnosis versus CBT (12 trials, N=602):] MWES=0.80 (SE=0.09, 95% CI: 0.62 to 0.98); Significant effect (Z=8.89, P=0.001, two-tailed) | Positive | Low
Obesity/weight loss^40^; 10 studies/ 14 trials by Tx (N=882) | Secondary | --- | --- | ---
Obesity/weight loss^40^; 10 studies/ 14 trials by Tx (N=882) | Global | --- | --- | ---
Pain, disabilityrelated^41^; 10 (N=380) | Diagnosis-related | [underlined: Absolute treatment effectiveness compared to no treatment or education only:] medium weighted effect size = 0.53 (CI: 0.28 to 0.84); [underlined: Compared to other cognitive-behavioral treatments:] Not significant. Wide variation in the magnitude of individual effect sizes, including some positive findings | Unclear | Insufficient
Pain, disabilityrelated^41^; 10 (N=380) | Secondary | [underlined: Short-term psychological:] Reduced symptoms of depression (d=1.19), and improved perceived control over pain (d=0.54) immediately following hypnotherapy.; [underlined: Long-term psychological:] Small to medium non-significant effect size across individual psychological outcomes (3 to 6 months post-treatment) | Unclear | Insufficient
Pain, disabilityrelated^41^; 10 (N=380) | Global | --- | --- | ---
Postnatal depression^28^; 1 (N=63) | Diagnosis-related | [underlined: Risk of developing PND:] The SR found no studies meeting their inclusion criteria. | Unclear | Insufficient
Postnatal depression^28^; 1 (N=63) | Secondary | --- | --- | ---
Postnatal depression^28^; 1 (N=63) | Global | --- | --- | ---
PTSD^45^; 5 (N=383) | Diagnosis-related | [underlined: PTSD symptoms post-intervention (4 RCTs, N=160):] Favors hypnosis (d=1.17); [underlined: PTSD symptoms 4-wk follow-up (3 RCTs, N=108):] Favors hypnosis (d=1.58); [underlined: PTSD symptoms 12 & 16-18-wk follow-up (2 RCTs, N=66):] 12-wk favors hypnosis (d=0.93); 16-18 week favors hypnosis (d=2.44); [underlined: PTSD symptoms 12-month follow-up (1 RCT, N=36):] favors hypnosis (d=3.61); [underlined: PTSD symptoms 2 years (1 RCT, N=226):] favors hypnosis (d=0.66) | Unclear | Insufficient
PTSD^45^; 5 (N=383) | Secondary | --- | --- | ---
PTSD^45^; 5 (N=383) | Global | --- | --- | ---
Schizophrenia^47^; 3 (N=149 | Diagnosis-related | [underlined: Mental state:] nonsignificant differences | No effect | Low
Schizophrenia^47^; 3 (N=149 | Secondary | --- | --- | ---
Schizophrenia^47^; 3 (N=149 | Global | --- | --- | ---
Smoking cessation^48^; 11 (N=1,120) | Diagnosis-related | [underlined: Quit rates:] Most studies did not detect significant differences at 6 months or longer | No effect | Low
Smoking cessation^48^; 11 (N=1,120) | Secondary | --- | --- | ---
Smoking cessation^48^; 11 (N=1,120) | Global | --- | --- | ---

Abbreviations: CBT = cognitive-behavioral therapy; CCT = controlled clinical trial; CI = confidence interval; d= Cohen’s d; df = degrees of freedom; EMG = Electromyograph; HD = hemodialysis; MD = mean difference; MWES = mean weighted effect size; NICU = neonatal intensive care unit; P=p-value; PND = postnatal depression; PTSD = posttraumatic stress disorder; Q = q-value; RCT = randomized control trial; RD = risk difference; RR = risk ratio; SE = standard error; SR = systematic review; SMD = standard mean difference; Z = z-value