# APPENDIX C Assessment of Confidence in the Evidence from Systematic Reviews of Guided Imagery, Biofeedback, and Hypnosis

Table 5 Assessment of confidence in the evidence on guided imagery

Medical condition/target population | Outcome category | Sample size; 1: <=100; 2: 100-500; 3: 500+ | Consistency; 0: No major flaw; −1: Serious inconsistency | Directness; 0: No major flaw; −1: Limited applicability | Overall risk of bias; 0: Unclear/Low ROB; −1: High ROB | Sum of values: Confidence rating; ≤0: Insufficient; 1: Low; 2: Moderate; 3: High
Anxiety^16^ | Diagnosis-related | 1 | 0 | 0 | −1 | Insufficient
Anxiety^16^ | Secondary | 1 | 0 | 0 | −1 | Insufficient
Anxiety^16^ | Global | --- | --- | --- | --- | ---
Arthritis/rheumatic disease^20^ | Diagnosis-related | 2 | 0 | 0 | 0 | Moderate
Arthritis/rheumatic disease^20^ | Secondary | 1 | 0 | 0 | 0 | Low
Arthritis/rheumatic disease^20^ | Global | 1 | 0 | 0 | 0 | Low
Cancer^23^ | Diagnosis-related | 2 | 0 | 0 | −1 | Low
Cancer^23^ | Secondary | 2 | 0 | 0 | −1 | Low
Cancer^23^ | Global | 1 | 0 | 0 | −1 | Insufficient
Cardiac surgery^25^ | Diagnosis-related | 2 | −1 | 0 | 0 | Low
Cardiac surgery^25^ | Secondary | 2 | −1 | 0 | 0 | Low
Cardiac surgery^25^ | Global | --- | --- | --- | --- | ---
Critical illness/ICU^27^ | Diagnosis-related | 3 | −1 | 0 | −1 | Low
Critical illness/ICU^27^ | Secondary | 3 | −1 | 0 | −1 | Low
Critical illness/ICU^27^ | Global | --- | --- | --- | --- | ---
Fibromyalgia^3^ | Diagnosis-related | 2 | −1 | 0 | 0 | Low
Fibromyalgia^3^ | Secondary | 2 | 0 | 0 | −1 | Low
Fibromyalgia^3^ | Global | 1 | −1 | 0 | 0 | Insufficient
Headache^42^; 7 trials (N=400) | Diagnosis-related | 2 | 0 | −1 | −1 | Insufficient
Headache^42^; 7 trials (N=400) | Secondary | --- | --- | --- | --- | ---
Headache^42^; 7 trials (N=400) | Global | --- | --- | --- | --- | ---
Insomnia^34^ | Diagnosis-related | 2 | −1 | 0 | −1 | Insufficient
Insomnia^34^ | Secondary | --- | --- | --- | --- | ---
Insomnia^34^ | Global | --- | --- | --- | --- | ---
Menstrual disorders^39^ | Diagnosis-related | 2 | 0 | −1 | 0 | Low
Menstrual disorders^39^ | Secondary | --- | --- | --- | --- | ---
Menstrual disorders^39^ | Global | --- | --- | --- | --- | ---
Musculoskeletal pain^43^ | Diagnosis-related | 2 | 0 | −1 | −1 | Insufficient
Musculoskeletal pain^43^ | Secondary | --- | --- | --- | --- | ---
Musculoskeletal pain^43^ | Global | --- | --- | --- | --- | ---
Parkinson’s^44^ | Diagnosis-related | 1 | 0 | 0 | 0 | Low
Parkinson’s^44^ | Secondary | --- | --- | --- | --- | ---
Parkinson’s^44^ | Global | --- | --- | --- | --- | ---
Stroke^49^ | Diagnosis-related | 2 | −1 | 0 | 0 | Low
Stroke^49^ | Secondary | --- | --- | --- | --- | ---
Stroke^49^ | Global | --- | --- | --- | --- | ---

Abbreviations: CCT = Controlled clinical trial, GI = Guided imagery, ICU = Intensive care unit; ITT = Intention-to-treat; LOS = length of stay; MI = motor imagery; ROB = risk of bias, RCT = Randomized controlled trial; TTH = tension-type headache

Table 6 Assessment of confidence in the evidence on biofeedback

Medical condition or target population N controlled trials (N combined participants) | Outcome category | Sample size; 1: <=100; 2: 100-500; 3: 500+ | Consistency; 0: No major flaw; −1: Serious inconsistency | Directness; 0: No major flaw; −1: Limited applicability | Overall risk of bias; 0: Unclear or Low ROB; −1: High ROB | Sum of values: confidence rating; ≤0: Insufficient; 1: Low; 2: Moderate; 3: High
Balance/Gait training^15^; 8 (N=243) | Diagnosis-related | 2 | −1 | 0 | 0 | Low
Balance/Gait training^15^; 8 (N=243) | Secondary | 1 | −1 | 0 | 0 | Insufficient
Balance/Gait training^15^; 8 (N=243) | Global | 1 | 0 | 0 | 0 | Low
Bell’s Palsy^21^; 4 (N=118) | Diagnosis-related | 2 | −1 | −1 | 0 | Insufficient
Bell’s Palsy^21^; 4 (N=118) | Secondary | --- | --- | --- | --- | ---
Bell’s Palsy^21^; 4 (N=118) | Global | --- | --- | --- | --- | ---
Chronic ideopathic constipation^26^; 17 (N=931) | Diagnosis-related | 1 | 0 | 0 | −1 | Insufficient
Chronic ideopathic constipation^26^; 17 (N=931) | Secondary | --- | --- | --- | --- | ---
Chronic ideopathic constipation^26^; 17 (N=931) | Global | --- | --- | --- | --- | ---
Dysphagia^29^; 5 (N=141) | Diagnosis-related | 1 | −1 | 0 | −1 | Insufficient
Dysphagia^29^; 5 (N=141) | Secondary | --- | --- | --- | --- | ---
Dysphagia^29^; 5 (N=141) | Global | --- | --- | --- | --- | ---
Fecal incontinence^30^; 12 (N=approx. 350) | Diagnosis-related | 2 | 0 | 0 | 0 | Moderate
Fecal incontinence^30^; 12 (N=approx. 350) | Secondary | --- | --- | --- | --- | ---
Fecal incontinence^30^; 12 (N=approx. 350) | Global | --- | --- | --- | --- | ---
Fibromyalgia^31^; 7 (N=321) | Diagnosis-related | 2 | 0 | 0 | −1 | Low
Fibromyalgia^31^; 7 (N=321) | Secondary | 2 | 0 | 0 | −1 | Low
Fibromyalgia^31^; 7 (N=321) | Global | 2 | 0 | 0 | −1 | Low
Headache^13^; 94 (N=3500+) | Diagnosis-related | 3 | 0 | 0 | 0 | High
Headache^13^; 94 (N=3500+) | Secondary | 2 | 0 | 0 | 0 | Moderate
Headache^13^; 94 (N=3500+) | Global | 1 | 0 | 0 | 0 | Low
Hypertension^32^; 36 (N=1,660) | Diagnosis-related | 2 | 0 | 0 | −1 | Low
Hypertension^32^; 36 (N=1,660) | Secondary | --- | --- | --- | --- | ---
Hypertension^32^; 36 (N=1,660) | Global | --- | --- | --- | --- | ---
Intradialytic hypotension^33^; 8 (N=716) | Diagnosis-related | 2 | 0 | 0 | −1 | Low
Intradialytic hypotension^33^; 8 (N=716) | Secondary | 1 | −1 | 0 | −1 | Insufficient
Intradialytic hypotension^33^; 8 (N=716) | Global | 2 | −1 | 0 | −1 | Insufficient
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Diagnosis-related | 1 | 0 | −1 | 0 | Insufficient
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Secondary | --- | --- | --- | --- | ---
Knee osteoarthritis/Gait retraining^36^; 1 (N=56) | Global | --- | --- | --- | --- | ---
Labor/childbirth^37^; 4 (N=186) | Diagnosis-related | 2 | −1 | −1 | 0 | Insufficient
Labor/childbirth^37^; 4 (N=186) | Secondary | --- | --- | --- | --- | ---
Labor/childbirth^37^; 4 (N=186) | Global | --- | --- | --- | --- | ---
Raynaud’s^46^; 10 (N=531) | Diagnosis-related | 2 | −1 | −1 | −1 | Insufficient
Raynaud’s^46^; 10 (N=531) | Secondary | --- | --- | --- | --- | ---
Raynaud’s^46^; 10 (N=531) | Global | --- | --- | --- | --- | ---
Sleep bruxism^22^; 6 (N=126) | Diagnosis-related | 1 | −1 | 0 | −1 | Insufficient
Sleep bruxism^22^; 6 (N=126) | Secondary | 1 | −1 | 0 | −1 | Insufficient
Sleep bruxism^22^; 6 (N=126) | Global | --- | --- | --- | --- | ---
Stroke^14^; 18 (N=429) | Diagnosis-related | 2 | 0 | 0 | 0 | Moderate
Stroke^14^; 18 (N=429) | Secondary | --- | --- | --- | --- | ---
Stroke^14^; 18 (N=429) | Global | --- | --- | --- | --- | ---
Urinary incontinence in women^51^; 24 trials (N=1,583) | Diagnosis-related | 3 | −1 | 0 | −1 | Low
Urinary incontinence in women^51^; 24 trials (N=1,583) | Secondary | 2 | −1 | 0 | −1 | Insufficient
Urinary incontinence in women^51^; 24 trials (N=1,583) | Global | 2 | 0 | 0 | −1 | Low
Urinary incontinence after prostatectomy^50^; 13 (N=1,108) | Diagnosis-related | 3 | 0 | 0 | 0 | High
Urinary incontinence after prostatectomy^50^; 13 (N=1,108) | Secondary | --- | --- | --- | --- | ---
Urinary incontinence after prostatectomy^50^; 13 (N=1,108) | Global | 2 | 0 | 0 | 0 | Moderate

Abbreviations: ROB = risk of bias

Table 7 Assessment of confidence in the evidence on hypnosis

Medical condition or target population | Outcome category | Sample size; 1: <=100; 2: 100-500; 3: 500+ | Consistency; 0: No major flaw; −1: Serious inconsistency | Directness; 0: No major flaw; −1: Limited applicability | Overall risk of bias; 0: Unclear/Low ROB; −1: High ROB | Sum of values: Confidence rating; ≤0: Insufficient; 1: Low; 2: Moderate; 3: High
Anxiety^17^ | Diagnosis-related | 2 (14 trials, N=653) | 0 | 0 | −1 | Low
Anxiety^17^ | Secondary | --- | --- | --- | --- | ---
Anxiety^17^ | Global | --- | --- | --- | --- | ---
Anxiety, cancer^18^ | Diagnosis-related | 3 (20 trials, N=878) | −1 | 0 | −1 | Low
Anxiety, cancer^18^ | Secondary | --- | --- | --- | --- | ---
Anxiety, cancer^18^ | Global | --- | --- | --- | --- | ---
Anxiety, medical procedures^19^ | Diagnosis-related | 3 (18 trials, N=968) | −1 | 0 | −1 | Low
Anxiety, medical procedures^19^ | Secondary | --- | --- | --- | --- | ---
Anxiety, medical procedures^19^ | Global | --- | --- | --- | --- | ---
Breast cancer care^24^ | Diagnosis-related | 3 (13 trials, N=1,357) | −1 | 0 | −1 | Low
Breast cancer care^24^ | Secondary | --- | --- | --- | --- | ---
Breast cancer care^24^ | Global | --- | --- | --- | --- | ---
Fibromyalgia^3^ | Diagnosis-related | 1 (2 trials, N=95) | 0 | 0 | −1 | Insufficient
Fibromyalgia^3^ | Secondary | 1 (2 trials, N=95) | 0 | 0 | −1 | Insufficient
Fibromyalgia^3^ | Global | 1 (2 trials, N=95) | 0 | 0 | −1 | Insufficient
Insomnia^34^ | Diagnosis-related | 2 (6 trials, N=218) | 0 | 0 | −1 | Low
Insomnia^34^ | Secondary | --- | --- | --- | --- | ---
Insomnia^34^ | Global | --- | --- | --- | --- | ---
Irritable bowel syndrome^35^ | Diagnosis-related | 2 (8 trials, N=464) | 0 | 0 | 0 | Moderate
Irritable bowel syndrome^35^ | Secondary | 2 (N≤314) | −1 | 0 | 0 | Low
Irritable bowel syndrome^35^ | Global | 2 (5 trials, N=290) | −1 | 0 | 0 | Low
Labor/childbirth^38^; 9 (N=2,954) | Diagnosis-related | 3 (8 trials, N=2916) | −1 | −1 | −1 | Insufficient
Labor/childbirth^38^; 9 (N=2,954) | Secondary | 3 (6 trials, N=2361) | −1 | 0 | −1 | Low
Labor/childbirth^38^; 9 (N=2,954) | Global | --- | --- | --- | --- | ---
Obesity/weight loss^40^ | Diagnosis-related | 3 (10 trials, N=882) | −1 | 0 | −1 | Low
Obesity/weight loss^40^ | Secondary | --- | --- | --- | --- | ---
Obesity/weight loss^40^ | Global | --- | --- | --- | --- | ---
Pain, disability-related^41^ | Diagnosis-related | 2 (10 trials, N=380) | −1 | 0 | −1 | Insufficient
Pain, disability-related^41^ | Secondary | 2 (5 trials, N=180) | −1 | 0 | −1 | Insufficient
Pain, disability-related^41^ | Global | --- | --- | --- | --- | ---
Postnatal depression^28^ | Diagnosis-related | 1 (1 trials, N=63) | 0 | 0 | −1 | Insufficient
Postnatal depression^28^ | Secondary | --- | --- | --- | --- | ---
Postnatal depression^28^ | Global | --- | --- | --- | --- | ---
PTSD^45^ | Diagnosis-related | 2 (5 trials, N=383) | −1 | 0 | −1 | Insufficient
PTSD^45^ | Secondary | --- | --- | --- | --- | ---
PTSD^45^ | Global | --- | --- | --- | --- | ---
Schizophrenia^47^ | Diagnosis-related | 2 (3 trials, N=149) | 0 | 0 | −1 | Low
Schizophrenia^47^ | Secondary | --- | --- | --- | --- | ---
Schizophrenia^47^ | Global | --- | --- | --- | --- | ---
Smoking cessation^48^ | Diagnosis-related | 3 (11 trials, N=1,120) | −1 | 0 | −1 | Low
Smoking cessation^48^ | Secondary | --- | --- | --- | --- | ---
Smoking cessation^48^ | Global | --- | --- | --- | --- | ---

Abbreviations: ROB = risk of bias