# APPENDIX B Study Selection

## Inclusion codes, code definitions, and criteria

1. Is the full-text of the article in English?
  - Yes → Proceed to 2.
  - No → STOP. Code X1 (Non-English language publication).
2. Does the population include adults (aged 18+) with a specified health condition?
  - Yes → Proceed to 3.
  - No → STOP. Code X2 (Excluded population)
  - Note: a study that includes both children and adults may be included if it represents the best or only evidence for a particular health condition.
3. Does the intervention include guided imagery, biofeedback, or hypnosis, and report results specific to the intervention? Studies of guided imagery, biofeedback, or hypnosis as an adjunct therapy that report the additional effects of the intervention, compared with a study arm containing the primary therapy by itself, are included.
  - Yes → Proceed to 4.
  - Guided imagery:
  - Include:
    - autogenic training
    - guided meditation
    - integrative restoration (iRest)
    - Katathym-imaginative Psychotherapy
    - mental imagery
    - mental practice
    - mental rehearsal
    - motor imagery
    - nightmare rescripting
    - yoga Nidra
  - Exclude: virtual reality; mirror therapy
  - Biofeedback: also “neurofeedback,” and “neurotherapy”
  - Include: interventions that generate physiological values or data points that are fed back to the user.
  - Exclude: Studies of biofeedback as part of a complex or multicomponent intervention.
  - Hypnosis: also “hypnotherapy”.
  - No → STOP. Code X3 (Not relevant to topic)
4. Is the study design a systematic review or meta-analysis that includes controlled clinical trials (either randomized or non-randomized) with guided imagery, biofeedback, or hypnosis intervention as its main focus? Reviews that do not conduct a comprehensive search (eg, only one electronic database), or do not assess study quality using validated criteria are excluded. Good-quality meta-reviews are included.
  - Yes → Proceed to 5.
  - No → STOP. Code X4 (Excluded study design or publication type)
  - Exclude: Narrative or non-systematic review, critical review, scoping review, opinion/editorial, or primary study.
    - B code instructions: Mark any excludes that we should reference later B
    - Examples:
    - B-X3 – Narrative review with good background
    - B-X3 – May be useful for discussion
5. Indicate the intervention type by entering the KQ#, using multiple KQ#s as needed:
  a. Guided imagery: KQ1.
  b. Biofeedback: KQ2.
  c. Hypnosis: KQ3.
6. Indicate the population by entering health condition eg, “KQ2 - Fibromyalgia”