# APPENDIX A Search Strategies

## Ovid MEDLINE(R) Epub Ahead of Print, In-Process & Other Non-Indexed Citations, Ovid MEDLINE(R) Daily and Ovid MEDLINE(R) 1946 to Present

Date Searched: March 14, 2018

Searched by: Robin Paynter, MLIS

| Searches | Results
1 | “Imagery (Psychotherapy)”/ | 1528
2 | (((guided or relaxation or reverie) adj3 (imagery or therapy)) or (mind adj2 body) or “Katathym-imaginative Psychotherapy”).tw,kf. | 10066
3 | or/1-2 | 11235
4 | biofeedback, psychology/ or neurofeedback/ | 7426
5 | (biofeedback or neurofeedback).tw,kf. | 7121
6 | or/4-5 | 10378
7 | hypnosis, anesthetic/ or hypnosis/ | 9135
8 | (hypnosis or hypnotherap* or self-hypno*).tw,kf. | 8400
9 | or/7-8 | 11593
10 | pain/ or pain management/ or abdominal pain/ or abdomen, acute/ or acute pain/ or arthralgia/ or shoulder pain/ or back pain/ or failed back surgery syndrome/ or low back pain/ or breakthrough pain/ or cancer pain/ or chest pain/ or angina pectoris/ or angina, unstable/ or angina, stable/ or chronic pain/ or earache/ or eye pain/ or facial pain/ or toothache/ or flank pain/ or glossalgia/ or headache/ or slit ventricle syndrome/ or labor pain/ or mastodynia/ or metatarsalgia/ or morton neuroma/ or musculoskeletal pain/ or myalgia/ or pelvic girdle pain/ or neck pain/ or neuralgia/ or neuralgia, postherpetic/ or piriformis muscle syndrome/ or pudendal neuralgia/ or sciatica/ or nociceptive pain/ or visceral pain/ or pain, intractable/ or pain, postoperative/ or phantom limb/ or pain, procedural/ or pain, referred/ or pelvic pain/ or dysmenorrhea/ or renal colic/ | 359439
11 | (pain* or angina or appendicitis or arthralgia* or arthrit* or “broken bone*” or dysmenorrhea* or earache* or endometriosis or fasciitis or fibromyalgia* or “frozen shoulder” or glossalgia* or gout* or headache* or lupus or mastodynia or metatarsalgia* or neuroma* or migraine* or myalgia* or neuralgia* or neuropath* or nociceptive or osteoarthriti* or pancreatitis* or “phantom limb” or postamputation* or post-amputation* or “renal colic” or sciatica* or shingles or “sickle cell” or “slipped disc” or toothache*).tw,kf. | 1185918
12 | or/10-11 | 1275970
13 | and/3,12 | 1520
14 | limit 13 to (meta analysis or systematic reviews) | 192
15 | and/6,12 | 1951
16 | limit 15 to (meta analysis or systematic reviews) | 182
17 | and/9,12 | 1843
18 | limit 17 to (meta analysis or systematic reviews) | 144
19 | mental health/ or mental disorders/ or anxiety disorders/ or agoraphobia/ or anxiety, separation/ or neurocirculatory asthenia/ or neurotic disorders/ or obsessive-compulsive disorder/ or hoarding disorder/ or panic disorder/ or phobic disorders/ or phobia, social/ or “bipolar and related disorders”/ or bipolar disorder/ or “disruptive, impulse control, and conduct disorders”/ or firesetting behavior/ or gambling/ or trichotillomania/ or dissociative disorders/ or multiple personality disorder/ or elimination disorders/ or encopresis/ or enuresis/ or diurnal enuresis/ or nocturnal enuresis/ or “feeding and eating disorders”/ or anorexia nervosa/ or binge-eating disorder/ or bulimia nervosa/ or “feeding and eating disorders of childhood”/ or female athlete triad syndrome/ or food addiction/ or night eating syndrome/ or pica/ or mood disorders/ or depressive disorder/ or depression, postpartum/ or depressive disorder, major/ or depressive disorder, treatment-resistant/ or dysthymic disorder/ or premenstrual dysphoric disorder/ or seasonal affective disorder/ or cyclothymic disorder/ or motor disorders/ or neurocognitive disorders/ or amnesia/ or alcoholic korsakoff syndrome/ or amnesia, anterograde/ or amnesia, retrograde/ or amnesia, transient global/ or cognition disorders/ or auditory perceptual disorders/ or huntington disease/ or cognitive dysfunction/ or consciousness disorders/ or delirium/ or emergence delirium/ or dementia/ or aids dementia complex/ or alzheimer disease/ or aphasia, primary progressive/ or primary progressive nonfluent aphasia/ or creutzfeldt-jakob syndrome/ or dementia, vascular/ or dementia, multi-infarct/ or diffuse neurofibrillary tangles with calcification/ or frontotemporal lobar degeneration/ or frontotemporal dementia/ or “pick disease of the brain”/ or kluver-bucy syndrome/ or lewy body disease/ or dyslexia, acquired/ or alexia, pure/ or neurodevelopmental disorders/ or “attention deficit and disruptive behavior disorders”/ or attention deficit disorder with hyperactivity/ or conduct disorder/ or communication disorders/ or social communication disorder/ or speech sound disorder/ or developmental disabilities/ or intellectual disability/ or learning disorders/ or dyscalculia/ or dyslexia/ or specific learning disorder/ or motor skills disorders/ or mutism/ or reactive attachment disorder/ or stereotypic movement disorder/ or tic disorders/ or tourette syndrome/ or paraphilic disorders/ or exhibitionism/ or “fetishism (psychiatric)”/ or masochism/ or pedophilia/ or sadism/ or transvestism/ or voyeurism/ or personality disorders/ or antisocial personality disorder/ or borderline personality disorder/ or compulsive personality disorder/ or dependent personality disorder/ or histrionic personality disorder/ or hysteria/ or paranoid personality disorder/ or passive-aggressive personality disorder/ or schizoid personality disorder/ or schizotypal personality disorder/ or “schizophrenia spectrum and other psychotic disorders”/ or affective disorders, psychotic/ or capgras syndrome/ or delusional parasitosis/ or morgellons disease/ or paranoid disorders/ or psychotic disorders/ or psychoses, substance-induced/ or psychoses, alcoholic/ or schizophrenia/ or schizophrenia, catatonic/ or schizophrenia, disorganized/ or schizophrenia, paranoid/ or shared paranoid disorder/ or sexual dysfunctions, psychological/ or dyspareunia/ or erectile dysfunction/ or gender dysphoria/ or premature ejaculation/ or “sexual and gender disorders”/ or vaginismus/ or sleep wake disorders/ or dyssomnias/ or sleep deprivation/ or sleep disorders, circadian rhythm/ or jet lag syndrome/ or sleep disorders, intrinsic/ or “disorders of excessive somnolence”/ or hypersomnolence, idiopathic/ or kleine-levin syndrome/ or narcolepsy/ or cataplexy/ or restless legs syndrome/ or “sleep initiation and maintenance disorders”/ or parasomnias/ or nocturnal paroxysmal dystonia/ or rem sleep parasomnias/ or rem sleep behavior disorder/ or sleep paralysis/ or sleep arousal disorders/ or night terrors/ or somnambulism/ or sleep bruxism/ or sleep-wake transition disorders/ or somatoform disorders/ or body dysmorphic disorders/ or conversion disorder/ or factitious disorders/ or munchausen syndrome/ or munchausen syndrome by proxy/ or hypochondriasis/ or neurasthenia/ or substance-related disorders/ or alcohol-related disorders/ or alcohol amnestic disorder/ or alcohol withdrawal delirium/ or alcoholic intoxication/ or alcoholism/ or binge drinking/ or wernicke encephalopathy/ or amphetamine-related disorders/ or cocaine-related disorders/ or inhalant abuse/ or marijuana abuse/ or “marijuana use”/ or neonatal abstinence syndrome/ or opioid-related disorders/ or morphine dependence/ or opium dependence/ or phencyclidine abuse/ or substance abuse, intravenous/ or substance abuse, oral/ or substance withdrawal syndrome/ or “tobacco use disorder”/ or “trauma and stressor related disorders”/ or adjustment disorders/ or stress disorders, traumatic/ or battered child syndrome/ or combat disorders/ or psychological trauma/ or stress disorders, post-traumatic/ or stress disorders, traumatic, acute/ | 1099654
20 | (“mental health” or “mental* ill*” or “mental disorder*” or “anxiety disorder*” or “agoraphobia” or neurotic or neurosis or neuroses or obsessive-compulsive or hoarding or “panic disorder” or “phobic disorder*” or “bipolar disorder” or manic-depress* or “conduct disorder*” or “firesetting behavior” or gambling or “dissociative disorder*” or “multiple personality disorder” or “elimination disorder*” or encopresis or enuresis or “eating disorder*” or “anorexia nervosa” or “binge-eating disorder” or “bulimia nervosa” or “food addiction” or “mood disorder*” or “depressive disorder” or “post-partum depression” or “major depression” or “dysthymic disorder” or “premenstrual dysphoric disorder” or “seasonal affective disorder” or “cyclothymic disorder” or “motor disorder*” or “neurocognitive disorder*” or “amnesia” or “cognition disorder*” or “auditory perceptual disorder*” or “huntington* disease” or “cognitive dysfunction” or “consciousness disorder*” or delirium or dementia* or “alzheimer* disease” or aphasia or “creutzfeldt-jakob syndrome” or “kluver-bucy syndrome” or “lewy body disease” or dyslexia or “neurodevelopmental disorder*” or “attention deficit and disruptive behavior disorder*” or “attention deficit disorder” or “ADD” or “attention deficit disorder with hyperactivity” or ADHD or “communication disorder*” or “speech sound disorder” or “developmental disabilit*” or “intellectual disabilit*” or “learning disorder*” or “reactive attachment disorder” or “tic disorder*” or “tourette* syndrome” or “paraphilic disorder*” or exhibitionism or fetishism or masochism or pedophilia or sadism or transvest* or voyeuris* or “personality disorder*” or hysteria or schizophreni* or “psychotic disorder*” or “affective disorder*” or “paranoid disorder*” or psychoses or “sexual dysfunction*” or dyspareunia or “erectile dysfunction” or “gender dysphoria” or “premature ejaculation” or “sexual* disorder*” or “gender disorder*” or vaginismus or “sleep wake disorder*” or dyssomnia* or “sleep disorder*” or “jet lag syndrome” or “excessive somnolence” or hypersomnolence or narcolep* or cataplex* or “restless legs syndrome” or parasomnia* or “nocturnal paroxysmal dystonia” or “rem sleep behavior disorder” or “sleep paralysis” or “sleep arousal disorder*” or “night terror*” or somnambulism or “sleep bruxism” or “sleep-wake transition disorder*” or “somatoform disorder*” or “body dysmorphic disorder*” or “conversion disorder” or “factitious disorder*” or “munchausen syndrome” or hypochondriasis or neurasthenia or “substance-related disorder*” or substance-abuse or drug-abuse or “alcohol-related disorder*” or alcohol-abuse or alcoholism or “alcohol withdrawal delirium” or “binge drinking” or “amphetamine-related disorder*” or amphetamine-abuse or methamphetamine-abuse or “cocaine-related disorders” or cocaine-abuse or “inhalant abuse” or “marijuana abuse” or “opioid-related disorder*” or opioid-abuse or opiate-abuse or morphine-dependence or morphine-abuse or opium-dependence or phencyclidine-abuse or “substance withdrawal syndrome” or “tobacco use disorder” or “adjustment disorder*” or “stress disorder*” or PTSD or “combat disorder*” or “psychological trauma”).tw,kf. | 888894
ESP21 | or/19-20 | 1427346
22 | and/3,21 | 1958
23 | limit 22 to (meta analysis or systematic reviews) | 155
24 | and/6,21 | 1576
25 | limit 24 to (meta analysis or systematic reviews) | 114
26 | and/9,21 | 2636
27 | limit 26 to (meta analysis or systematic reviews) | 92

## Ovid EBM Reviews - Cochrane Database of Systematic Reviews 2005 to March 21, 2018

Date Searched: March 27, 2018

Searched by: Robin Paynter, MLIS

# | Searches | Results
1 | ((guided adj3 (imagery or meditation* or visuali?ation*)) or mind-body or “Katathym-imaginative Psychotherapy”).ti,ab. | 9
2 | (biofeedback* or neurofeedback* or (autonomic* adj3 train*)).ti,ab. | 24
3 | (hypnosis or hypnotherap* or posthypnot* or post-hypnot* or self-hypno* or auto-hypno* or auto-hypno*).ti,ab. | 26
4 | or/1-3 | 51

## Ovid PsycINFO 1806 to March Week 3 2018

Date Searched: March 27, 2018

Searched by: Robin Paynter, MLIS

1 | Guided Imagery/ | 711
2 | ((guided adj3 (imagery or meditation* or visuali?ation*)) or mind-body or (imagery adj3 therap*) or “Katathym-imaginative Psychotherapy”).tw,id. | 6304
3 | biofeedback, psychology/ or neurofeedback/ | 1321
4 | (biofeedback* or neurofeedback* or (autonomic* adj3 train*)).tw,id. | 6508
5 | hypnosis/ or autohypnosis/ or hypnotherapy/ | 10915
6 | (hypnosis or hypnotherap* or posthypnot* or post-hypnot* or self-hypno* or autohypno* or autohypno*).tw,id. | 15548
7 | or/1-6 | 29722
8 | limit 7 to (“0830 systematic review” or 1200 meta analysis) | 209
9 | remove duplicates from 8 | 209

* * * * * * * * *

## EBSCOhost CINAHL Plus with Full Text

Date searched: March 28, 2018

Searched by: Robin Paynter, MLIS

# | Search | Result
S7 | S1 OR S2 OR S3 OR S4 OR S5 OR S6; Limiters - Exclude MEDLINE records;; Publication Type: Meta Analysis, Systematic Review | 205
S6 | TI (hypnosis OR hypnotherap* OR hypno-therap* OR posthypnot* OR post-hypnot* OR self-hypno* OR autohypno* OR auto-hypno*) OR AB (hypnosis OR hypnotherap* OR hypno-therap* OR posthypnot* OR post-hypnot* OR self-hypno* OR autohypno* OR auto-hypno*) | 1,950
S5 | (MH “Hypnosis”) OR (MH “Hypnosis, Anesthetic”) OR (MH “Hypnosis (Iowa NIC)”) OR (MH “Posthypnotic Suggestion”) | 2,611
S4 | TI (biofeedback* OR bio-feedback* OR neurofeedback* OR neuro-feedback* OR (autonomic* N3 train*)) OR AB (biofeedback* OR bio-feedback* OR neurofeedback* OR neuro-feedback* OR (autonomic* N3 train*?)) | 2,428
S3 | (MH “Biofeedback”) OR (MH “Biofeedback (Iowa NIC)”) | 3,170
S2 | TI ((guided N3 (imagery OR meditation* OR visuali#ation*)) OR mind-body OR “imagery N3 therap*” OR “Katathym-imaginative Psychotherapy”) OR AB ((guided N3 (imagery OR meditation* OR visuali#ation*)) OR mind-body OR “imagery N3 therap*” OR “Katathym-imaginative Psychotherapy”) | 2,515
S1 | (MH “Guided Imagery”) OR (MH “Simple Guided Imagery (Iowa NIC)”) | 2,364

* * * * * * * *

## Epistemonikos (https://www.epistemonikos.org)

Date Searched: March 28, 2018

Searched by: Robin Paynter, MLIS

(Title, abstract) “guided imagery” OR “guided meditation*” OR “guided visualization*” OR “guided visualisation*” or mind-body or “mind body” or “Katathym-imaginative Psychotherapy”

(Title, abstract) biofeedback* OR neurofeedback* OR “autonomic* train*”

(Title, abstract) hypnosis OR hypnotherap* OR hypno-therap* OR posthypnot* OR post-hypnot* OR self-hypno* OR auto-hypno* OR autohypno*

Limit: publication type = systematic review

## Ovid MEDLINE(R) and Epub Ahead of Print, In-Process & Other Non-Indexed Citations and Daily 1946 to September 24, 2018

Date Searched: September 25, 2018

Searched by: Robin Paynter, MLIS

# | Searches | Results
1 | “Imagery (Psychotherapy)”/ | 1598
2 | ((guided adj3 (imagery or meditation* or visuali!ation*)) or (autogenic* adj3 train*) or (imagery adj3 therap*) or “integrative restoration” or (irest not “international reading speed”) or “Katathym-imaginative Psychotherapy” or “mental practice” or “mental rehearsal” or “mind-body” or “yoga nidra”).tw,kf. | 4545
3 | biofeedback, psychology/ or neurofeedback/ | 7576
4 | ((autonomic* adj3 train*) or biofeedback* or bio-feedback* or neurofeedback* or neuro-feedback* or neurotherap* or neuro-therap*).tw,kf. | 8149
5 | hypnosis, anesthetic/ or hypnosis/ | 9224
6 | (autohypno* or auto-hypno* or hypnosis or hypnot* or hypnotherap* or hypno-therap* or posthypnot* or post-hypnot* or selfhypno* or self-hypno*).tw,kf. | 21907
7 | or/1-6 | 39811
8 | limit 7 to (meta analysis or systematic reviews) | 1538
9 | (adolescent/ or exp child/ or exp infant/) not exp adult/ | 1762065
10 | 8 not 9 | 1417
11 | Meta-Analysis as Topic/ | 16427
12 | meta analy$.tw. | 133311
13 | metaanaly$.tw. | 1866
14 | Meta-Analysis/ | 92394
15 | (systematic adj (review$1 or overview$1)).tw. | 127604
16 | exp Review Literature as Topic/ | 10064
17 | or/11-16 | 239570
18 | cochrane.ab. | 63762
19 | embase.ab. | 68016
20 | (psycinfo or psychinfo or psyclit or psychlit).ab. | 25518
21 | (cinahl or cinhal).ab. | 21693
22 | science citation index.ab. | 2806
23 | bids.ab. | 463
24 | cancerlit.ab. | 622
25 | or/18-24 | 111651
26 | reference list$.ab. | 15634
27 | bibliograph$.ab. | 16048
28 | hand-search$.ab. | 6019
29 | relevant journals.ab. | 1063
30 | manual search$.ab. | 3845
31 | or/26-30 | 38166
32 | selection criteria.ab. | 27412
33 | data extraction.ab. | 16815
34 | or/32-33 | 42134
35 | Review/ | 2430793
36 | and/34-35 | 28180
37 | Comment/ | 733437
38 | Letter/ | 1000623
39 | Editorial/ | 468641
40 | animal/ | 6269186
41 | human/ | 17289997
42 | 40 not (40 and 41) | 4464396
43 | or/37-39,42 | 6062191
44 | 17 or 25 or 31 or 36 | 288530
45 | 44 not 43 | 273772
46 | and/7,45 | 1285
47 | or/10,46 | 1727
48 | remove duplicates from 47 | 1693