# Acknowledgments

This topic was developed in response to a nomination the Office of Patient Centered Care and Cultural Transformation (OPCC&CT) to guide the use of guided imagery, biofeedback, and hypnosis in the VHA. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge Robin Paynter, MLIS, Jessica Montgomery, MPH, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Ben Kligler, MD, MPH
  National Director, Coordinating Center for Integrative Health (10NE)
  VACO, Washington, DC
- Laura Krejci, MSW
  Associate Director, Office of Patient Centered Care and Cultural Transformation
  VACO, Washington, DC

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Jeffrey Bolek, PhD
  Motor Control Restoration L.L.C.
  Cleveland, OH
- Jack P. Ginsberg, PhD
  Dorn VA Medical Center
  USC School of Medicine
  Columbia, SC
- David Hagedorn, PhD, BCN
  Evoke Neuroscience
  New York, NY
- Guy Montgomery, PhD
  Icahn School of Medicine at Mount Sinai
  New York, NY
- Belleruth Naparstek, ACSW
  Healthjourneys
  Cleveland, OH
- Chris Suhar, MD
  Scripps Center for Integrative Medicine
  La Jolla, CA
- David Spiegel, MD
  Stanford University School of Medicine
  Stanford, CA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.