# REFERENCES

1 Siegel RL, Miller KD, Fuchs HE, Cancer statistics, 2022. CA Cancer J Clin. 2022;72(1):7–33.35020204
2 Zullig LL, Jackson GL, Dorn RA, Cancer incidence among patients of the U.S. Veterans Affairs Health Care System. Mil Med. 2012;177(6):693–701.22730846
3 D'Amico AV, Whittington R, Malkowicz SB, Biochemical outcome after radical prostatectomy, external beam radiation therapy, or interstitial radiation therapy for clinically localized prostate cancer. JAMA. 1998;280(11):969–74.9749478
4 Cuzick J, Swanson GP, Fisher G, Prognostic value of an RNA expression signature derived from cell cycle proliferation genes in patients with prostate cancer: a retrospective study. Lancet Oncology. 2011;12(3):245–55.21310658
5 Knezevic D, Goddard AD, Natraj N, Analytical validation of the Oncotype DX prostate cancer assay - a clinical RT-PCR assay optimized for prostate needle biopsies. BMC Genomics. 2013;14:690.24103217
6 Erho N, Crisan A, Vergara IA, Discovery and validation of a prostate cancer genomic classifier that predicts early metastasis following radical prostatectomy. PLoS One. 2013;8(6):e66855.23826159
7 Two Studies for Patients With High Risk Prostate Cancer Testing Less Intense Treatment for Patients With a Low Gene Risk Score and Testing a More Intense Treatment for Patients With a High Gene Risk Score, The PREDICT-RT Trial. Available at: https://clinicaltrials.gov/ct2/show/NCT04513717. Accessed January 16, 2023.
8 Two Studies for Patients With Unfavorable Intermediate Risk Prostate Cancer Testing Less Intense Treatment for Patients With a Low Gene Risk Score and Testing a More Intense Treatment for Patients With a Higher Gene Risk Score. Available at: https://clinicaltrials.gov/ct2/show/NCT05050084. Accessed January 16, 2023.
9 McGowan J, Sampson M, Salzwedel DM, PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
10 Riley RD, Moons KG M, Snell KI E, A guide to systematic review and meta-analysis of prognostic factor studies. Bmj. 2019;364:k4597.30700442
11 Hayden JA, van der Windt DA, Cartwright JL, Assessing bias in studies of prognostic factors. Ann Intern Med. 2013;158(4):280–6.23420236
12 Grooten WJ A, Tseli E, Äng BO, Elaborating on the assessment of the risk of bias in prognostic studies in pain rehabilitation using QUIPS-aspects of interrater agreement. Diagn Progn Res. 2019;3:5.31093575
13 Sterne JA C, Savović J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. Bmj. 2019;366:l4898.31462531
14 Sterne JA, Hernán MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. 2016;355:i4919.27733354
15 Iorio A, Spencer FA, Falavigna M, Use of GRADE for assessment of evidence about prognosis: rating confidence in estimates of event rates in broad categories of patients. Bmj. 2015;350:h870.25775931
16 Seiden B, Weng S, Sun N, NCCN Risk Reclassification in Black Men with Low and Intermediate Risk Prostate Cancer After Genomic Testing. Urology. 2021;22:22.
17 Gaffney C, Golan R, Cantu MD, The Clinical Utility of the Genomic Prostate Score in Men with Very Low to Intermediate Risk Prostate Cancer. Journal of Urology. 2019;202(1):96–101.30933552
18 Lynch JA, Rothney MP, Salup RR, Improving risk stratification among veterans diagnosed with prostate cancer: impact of the 17-gene prostate score assay. American Journal of Managed Care. 2018;24(1 Suppl):S4–S10.29337486
19 Spratt DE, Zhang J, Santiago-Jimenez M, Development and Validation of a Novel Integrated Clinical-Genomic Risk Group Classification for Localized Prostate Cancer. Journal of Clinical Oncology. 2018;36(6):581–590.29185869
20 Eure G, Germany R, Given R, Use of a 17-Gene Prognostic Assay in Contemporary Urologic Practice: Results of an Interim Analysis in an Observational Cohort. Urology. 2017;107:67–75.28454985
21 Oderda M, Cozzi G, Daniele L, Cell-cycle Progression-score Might Improve the Current Risk Assessment in Newly Diagnosed Prostate Cancer Patients. Urology. 2017;102:73–78.27894974
22 Klein EA, Haddad Z, Yousefi K, Decipher Genomic Classifier Measured on Prostate Biopsy Predicts Metastasis Risk. Urology. 2016;90:148–52.26809071
23 Murphy AB, Abern MR, Liu L, Impact of a genomic test on treatment decision in a predominantly African American population with favorable-risk prostate cancer: A randomized trial. Journal of Clinical Oncology. 2021;39(15):1660–1670.33835822
24 Badani KK, Kemeter MJ, Febbo PG, The Impact of a Biopsy Based 17-Gene Genomic Prostate Score on Treatment Recommendations in Men with Newly Diagnosed Clinically Prostate Cancer Who are Candidates for Active Surveillance. Urology Practice. 2015;2(4):181–189.37559258
25 Rayford W, Greenberger M, Bradley RV. Improving risk stratification in a community-based African American population using cell cycle progression score. Translational Andrology & Urology. 2018;7(Suppl 4):S384–S391.30363476
26 Michalopoulos SN, Kella N, Payne R, Influence of a genomic classifier on post-operative treatment decisions in high-risk prostate cancer patients: results from the PRO-ACT study. Current Medical Research & Opinion. 2014;30(8):1547–56.24803160
27 Gore JL, du Plessis M, Zhang J, Clinical Utility of a Genomic Classifier in Men Undergoing Radical Prostatectomy: The PRO-IMPACT Trial. Practical Radiation Oncology. 2020;10(2):e82–e90.31761540
28 Nguyen PL, Shin H, Yousefi K, Impact of a Genomic Classifier of Metastatic Risk on Postprostatectomy Treatment Recommendations by Radiation Oncologists and Urologists. Urology. 2015;86(1):35–40.26142578
29 Badani KK, Thompson DJ, Brown G, Effect of a genomic classifier test on clinical practice decisions for patients with high-risk prostate cancer after surgery. BJU International. 2015;115(3):419–29.24784420
30 Badani K, Thompson DJ, Buerki C, Impact of a genomic classifier of metastatic risk on postoperative treatment recommendations for prostate cancer patients: a report from the DECIDE study group. Oncotarget. 2013;4(4):600–9.23592338
31 Canfield S, Kemeter MJ, Hornberger J, Active Surveillance Use Among a Low-risk Prostate Cancer Population in a Large US Payer System: 17-Gene Genomic Prostate Score Versus Other Risk Stratification Methods. Reviews in Urology. 2017;19(4):203–212.29472824
32 Dall'Era MA, Maddala T, Polychronopoulos L, Utility of the Oncotype DX^®^ Prostate Cancer Assay in Clinical Practice for Treatment Selection in Men Newly Diagnosed with Prostate Cancer: A Retrospective Chart Review Analysis. Urology Practice. 2015;2(6):343–348.37559290
33 Morris DS, Woods JS, Edwards B, Prognostic capabilities and clinical utility of cell cycle progression testing, prostate imaging reporting and data system, version 2, and clinicopathologic data in management of localized prostate cancer. Urologic Oncology. 2021;39(6):366.e19-366.e28.
34 Crawford ED, Scholz MC, Kar AJ, Cell cycle progression score and treatment decisions in prostate cancer: results from an ongoing registry. Current Medical Research & Opinion. 2014;30(6):1025–31.24576172
35 Shore ND, Kella N, Moran B, Impact of the Cell Cycle Progression Test on Physician and Patient Treatment Selection for Localized Prostate Cancer. J Urol. 2016;195(3):612–8.26403586
36 Gore JL, du Plessis M, Santiago-Jimenez M, Decipher test impacts decision making among patients considering adjuvant and salvage treatment after radical prostatectomy: Interim results from the Multicenter Prospective PRO-IMPACT study. Cancer. 2017;123(15):2850–2859.28422278
37 Shahait M, Liu VY T, Vapiwala N, Impact of Decipher on use of post-operative radiotherapy: Individual patient analysis of two prospective registries. BJUI Compass. 2021;2(4):267–274.35475294
38 Vince RA Jr., Jiang R, Qi J, Impact of Decipher Biopsy testing on clinical outcomes in localized prostate cancer in a prospective statewide collaborative. Prostate Cancer & Prostatic Diseases. 2021;20:20.
39 Brooks MA, Thomas L, Magi-Galluzzi C, GPS Assay Association With Long-Term Cancer Outcomes: Twenty-Year Risk of Distant Metastasis and Prostate Cancer-Specific Mortality. JCO Precision Oncology. 2021;5.
40 Lehto TK, Sturenberg C, Malen A, Transcript analysis of commercial prostate cancer risk stratification panels in hard-to-predict grade group 2–4 prostate cancers. Prostate. 2021;81(7):368–376.33734461
41 Feng FY, Huang HC, Spratt DE, Validation of a 22-Gene Genomic Classifier in Patients With Recurrent Prostate Cancer: An Ancillary Study of the NRG/RTOG 9601 Randomized Clinical Trial. JAMA Oncology. 2021;7(4):544–552.33570548
42 Ramotar M, Chua ML K, Truong H, Subpathologies and genomic classifier for treatment individualization of post-prostatectomy radiotherapy. Urologic Oncology. 2022;40(1):5.e1-5.e13.
43 Tosoian JJ, Birer SR, Jeffrey Karnes R, Performance of clinicopathologic models in men with high risk localized prostate cancer: impact of a 22-gene genomic classifier. Prostate Cancer & Prostatic Diseases. 2020;23(4):646–653.32231245
44 Howard LE, Zhang J, Fishbane N, Validation of a genomic classifier for prediction of metastasis and prostate cancer-specific mortality in African-American men following radical prostatectomy in an equal access healthcare setting. Prostate Cancer & Prostatic Diseases. 2020;23(3):419–428.31844180
45 Shangguan X, Qian H, Jiang Z, Cell cycle progression score improves risk stratification in prostate cancer patients with adverse pathology after radical prostatectomy. Journal of Cancer Research & Clinical Oncology. 2020;146(3):687–694.31745702
46 Canter DJ, Freedland S, Rajamani S, Analysis of the prognostic utility of the cell cycle progression (CCP) score generated from needle biopsy in men treated with definitive therapy. Prostate Cancer & Prostatic Diseases. 2020;23(1):102–107.31243337
47 Kornberg Z, Cooperberg MR, Cowan JE, A 17-Gene Genomic Prostate Score as a Predictor of Adverse Pathology in Men on Active Surveillance. Journal of Urology. 2019;202(4):702–709.31026214
48 Canter DJ, Reid J, Latsis M, Comparison of the Prognostic Utility of the Cell Cycle Progression Score for Predicting Clinical Outcomes in African American and Non-African American Men with Localized Prostate Cancer. European Urology. 2019;75(3):515–522.30391079
49 Berlin A, Murgic J, Hosni A, Genomic Classifier for Guiding Treatment of Intermediate-Risk Prostate Cancers to Dose-Escalated Image Guided Radiation Therapy Without Hormone Therapy. International Journal of Radiation Oncology, Biology, Physics. 2019;103(1):84–91.30170099
50 Leapman MS, Nguyen HG, Cowan JE, Comparing Prognostic Utility of a Single-marker Immunohistochemistry Approach with Commercial Gene Expression Profiling Following Radical Prostatectomy. European Urology. 2018;74(5):668–675.30181067
51 Leon P, Cancel-Tassin G, Drouin S, Comparison of cell cycle progression score with two immunohistochemical markers (PTEN and Ki-67) for predicting outcome in prostate cancer after radical prostatectomy. World Journal of Urology. 2018;36(9):1495–1500.29679140
52 Spratt DE, Dai DL Y, Den RB, Performance of a Prostate Cancer Genomic Classifier in Predicting Metastasis in Men with Prostate-specific Antigen Persistence Postprostatectomy. European Urology. 2018;74(1):107–114.29233664
53 Van Den Eeden SK, Lu R, Zhang N, A Biopsy-based 17-gene Genomic Prostate Score as a Predictor of Metastases and Prostate Cancer Death in Surgically Treated Men with Clinically Localized Disease. European Urology. 2018;73(1):129–138.28988753
54 Karnes RJ, Choeurng V, Ross AE, Validation of a Genomic Risk Classifier to Predict Prostate Cancer-specific Mortality in Men with Adverse Pathologic Features. European Urology. 2018;73(2):168–175.28400167
55 Nguyen PL, Haddad Z, Ross AE, Ability of a Genomic Classifier to Predict Metastasis and Prostate Cancer-specific Mortality after Radiation or Surgery based on Needle Biopsy Specimens. European Urology. 2017;72(5):845–852.28528811
56 Tosoian JJ, Chappidi MR, Bishoff JT, Prognostic utility of biopsy-derived cell cycle progression score in patients with National Comprehensive Cancer Network low-risk prostate cancer undergoing radical prostatectomy: implications for treatment guidance. BJU International. 2017;120(6):808–814.28481440
57 Dalela D, Santiago-Jimenez M, Yousefi K, Genomic Classifier Augments the Role of Pathological Features in Identifying Optimal Candidates for Adjuvant Radiation Therapy in Patients With Prostate Cancer: Development and Internal Validation of a Multivariable Prognostic Model. Journal of Clinical Oncology. 2017;35(18):1982–1990.28350520
58 Nguyen PL, Martin NE, Choeurng V, Utilization of biopsy-based genomic classifier to predict distant metastasis after definitive radiation and short-course ADT for intermediate and high-risk prostate cancer. Prostate Cancer & Prostatic Diseases. 2017;20(2):186–192.28117383
59 Ross AE, Den RB, Yousefi K, Efficacy of post-operative radiation in a prostatectomy cohort adjusted for clinical and genomic risk. Prostate Cancer & Prostatic Diseases. 2016;19(3):277–82.27136742
60 Glass AG, Leo MC, Haddad Z, Validation of a Genomic Classifier for Predicting Post-Prostatectomy Recurrence in a Community Based Health Care Setting. Journal of Urology. 2016;195(6):1748–53.26626216
61 Ross AE, Johnson MH, Yousefi K, Tissue-based Genomics Augments Postprostatectomy Risk Stratification in a Natural History Cohort of Intermediate- and High-Risk Men. European Urology. 2016;69(1):157–65.26058959
62 Cuzick J, Stone S, Fisher G, Validation of an RNA cell cycle progression score for predicting death from prostate cancer in a conservatively managed needle biopsy cohort. British Journal of Cancer. 2015;113(3):382–9.26103570
63 Den RB, Yousefi K, Trabulsi EJ, Genomic classifier identifies men with adverse pathology after radical prostatectomy who benefit from adjuvant radiation therapy. Journal of Clinical Oncology. 2015;33(8):944–51.25667284
64 Klein EA, Yousefi K, Haddad Z, A genomic classifier improves prediction of metastatic disease within 5 years after surgery in node-negative high-risk prostate cancer patients managed by radical prostatectomy without adjuvant therapy. European Urology. 2015;67(4):778–86.25466945
65 Cullen J, Rosner IL, Brand TC, A Biopsy-based 17-gene Genomic Prostate Score Predicts Recurrence After Radical Prostatectomy and Adverse Surgical Pathology in a Racially Diverse Population of Men with Clinically Low- and Intermediate-risk Prostate Cancer. European Urology. 2015;68(1):123–31.25465337
66 Cooperberg MR, Davicioni E, Crisan A, Combined value of validated clinical and genomic risk stratification tools for predicting prostate cancer mortality in a high-risk prostatectomy cohort. European Urology. 2015;67(2):326–33.24998118
67 Freedland SJ, Gerber L, Reid J, Prognostic utility of cell cycle progression score in men with prostate cancer after primary external beam radiation therapy. International Journal of Radiation Oncology, Biology, Physics. 2013;86(5):848–53.23755923
68 Cooperberg MR, Simko JP, Cowan JE, Validation of a cell-cycle progression gene panel to improve risk stratification in a contemporary prostatectomy cohort. Journal of Clinical Oncology. 2013;31(11):1428–34.23460710
69 Cuzick J, Berney DM, Fisher G, Prognostic value of a cell cycle progression signature for prostate cancer death in a conservatively managed needle biopsy cohort. British Journal of Cancer. 2012;106(6):1095–9.22361632
70 Bauman G, Breau RH, Kamel-Reid S, Ontario health technology assessment series: Prolaris cell cycle progression test for localized prostate cancer: A health technology assessment. 2017;17(6):1–75.
71 Bishoff JT, Freedland SJ, Gerber L, Prognostic utility of the cell cycle progression score generated from biopsy in men treated with prostatectomy. J Urol. 2014;192(2):409–14.24508632
72 Degeling K, Pereira-Salgado A, Corcoran NM, Health Economic Evidence for Liquid- and Tissue-based Molecular Tests that Inform Decisions on Prostate Biopsies and Treatment of Localised Prostate Cancer: A Systematic Review. European Urology Open Science. 2021;27:77–87.34337517
73 Lobo JM, Dicker AP, Buerki C, Evaluating the clinical impact of a genomic classifier in prostate cancer using individualized decision analysis. PLoS ONE [Electronic Resource]. 2015;10(3):e0116866.25837660
74 Caetano SJ, Sonpavde G, Pond GR. C-statistic: A brief explanation of its construction, interpretation and limitations. Eur J Cancer. 2018;90:130–132.29221899
75 Olleik G, Kassouf W, Aprikian A, Evaluation of New Tests and Interventions for Prostate Cancer Management: A Systematic Review. Journal of the National Comprehensive Cancer Network. 2018;16(11):1340–1351.30442734
76 Fine ND, LaPolla F, Epstein M, Genomic Classifiers for Treatment Selection in Newly Diagnosed Prostate Cancer. BJU International. 2019;04:04.
77 Health Quality Ontario. Prolaris Cell Cycle Progression Test for Localized Prostate Cancer: A Health Technology Assessment. Ontario Health Technology Assessment Series. 2017;17(6):1–75.
78 Bostrom PJ, Bjartell AS, Catto JW, Genomic Predictors of Outcome in Prostate Cancer. European Urology. 2015;68(6):1033–44.25913390
79 Lamy PJ, Allory Y, Gauchez AS, Prognostic Biomarkers Used for Localised Prostate Cancer Management: A Systematic Review. European Urology Focus. 2018;4(6):790–803.28753865
80 Spratt DE, Zumsteg ZS, Feng FY, Translational and clinical implications of the genetic landscape of prostate cancer. Nature Reviews Clinical Oncology. 2016;13(10):597–610.
81 Carrion DM, Rivas JG, Alvarez-Maestro M, BIOMARKERS IN PROSTATE CANCER MANAGEMENT. IS THERE SOMETHING NEW? Archivos Espanoles De Urologia. 2019;72(2):105–115.30855011
82 Jairath NK, Dal Pra A, Vince R Jr., A Systematic Review of the Evidence for the Decipher Genomic Classifier in Prostate Cancer. European Urology. 2021;79(3):374–383.33293078
83 Prolaris Enhanced Risk Stratification - an ecONomic and clinicAL Evaluation (PERSONAL). Available at: https://clinicaltrials.gov/ct2/show/study/NCT03851211. Accessed January 16, 2023.
84 Clinical Outcomes in Men With Prostate Cancer Who Selected Active Surveillance Using Prolaris^®^ Testing (URO-009Low). Available at: https://clinicaltrials.gov/ct2/show/results/NCT03511235. Accessed January 16, 2023.
85 Shore ND, Boczko J, Kella N, Impact of CCP test on personalizing treatment decisions: Results from a prospective registry of newly diagnosed prostate cancer patients. Journal of Clinical Oncology. 2015;33(7_suppl):63–63.
86 Registry to Measure the Impact of Adding Genomic Testing. Available at: https://clinicaltrials.gov/ct2/show/results/NCT02454595. Accessed January 16, 2023.
87 Mikhaylenko DS, Sergienko SA, Alekseev BY, Basic characteristics and features of the molecular genetic test systems designed for non-invasive diagnostics and prognosis of prostate cancer and bladder cancer. Onkourologiya. 2019;15(4):18–29.
88 Lillard JW Jr., Moses KA, Mahal BA, Racial disparities in Black men with prostate cancer: A literature review. Cancer. 2022;128(21):3787–3795.36066378
89 Dess RT, Hartman HE, Mahal BA, Association of Black Race With Prostate Cancer–Specific and Other-Cause Mortality. JAMA Oncology. 2019;5(7):975–983.31120534
90 Spratt DE, Huang H- C, Michalski JM, Validation of the performance of the Decipher biopsy genomic classifier in intermediate-risk prostate cancer on the phase III randomized trial NRG Oncology/RTOG 0126. Journal of Clinical Oncology. 2022;40(6_suppl):269–269.
91 Nguyen PL, Huang HR, Spratt DE, Analysis of a Biopsy-Based Genomic Classifier in High-Risk Prostate Cancer: Meta-Analysis of the NRG Oncology/Radiation Therapy Oncology Group 9202, 9413, and 9902 Phase 3 Randomized Trials. Int J Radiat Oncol Biol Phys. 2022.
92 Dal Pra A, Ghadjar P, Hayoz S, Validation of the Decipher genomic classifier in patients receiving salvage radiotherapy without hormone therapy after radical prostatectomy - an ancillary study of the SAKK 09/10 randomized clinical trial. Ann Oncol. 2022;33(9):950–958.35636621
93 Janes JL, Boyer MJ, Bennett JP, The 17-Gene Genomic Prostate Score Test Is Prognostic for Outcomes After Primary External Beam Radiation Therapy in Men With Clinically Localized Prostate Cancer. Int J Radiat Oncol Biol Phys. 2023;115(1):120–131.37574235
94 Attard G, Parry M, Grist E, Clinical testing of transcriptome-wide expression profiles in high-risk localized and metastatic prostate cancer starting androgen deprivation therapy: an ancillary study of the STAMPEDE abiraterone Phase 3 trial. Res Sq. 2023.
95 Spratt DE, Yousefi K, Deheshi S, Individual Patient-Level Meta-Analysis of the Performance of the Decipher Genomic Classifier in High-Risk Men After Prostatectomy to Predict Development of Metastatic Disease. Journal of Clinical Oncology. 2017;35(18):1991–1998.28358655