# ACKNOWLEDGMENTS

The authors are grateful to Liz Wing for editorial and citation management support, Katherine Van Loon for citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Edward Obedian, MD
  Chief, Radiation Oncology
  Bronx VA Hospital
- Michael G. Chang, MD
  Chief, Radiation Oncology
  Richmond VA Medical Center
- Maria Kelly, MD
  Executive Director
  National Radiation Oncology Program

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Daniel Spratt, MD
  Chair
  University Hospitals Cleveland Medical Center
  Department of Radiation Oncology
- Jeremy Shelton, MD, MSHS
  Director of Surgical Informatics/Chief of Telesurgery
  West Los Angeles VA Medical Center
  National Surgery Office
- Andrew J. Armstrong, MD, ScM, FACP
  Professor of Medicine, Surgery, Pharmacology and Cancer Biology Director of Research
  Duke Cancer Institute Center for Prostate and Urologic Cancers Divisions of Medical Oncology and Urology Duke University
- Eric Klein, MD
  Chairman
  Glickman Urological & Kidney Institute Taussig Cancer Institute, Cleveland Clinic

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix F for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.