# DISCUSSION

We evaluated the impact of 3 genomic classifier tests—Decipher, Oncotype, and Prolaris—on risk reclassification, treatment recommendations, and key clinical outcomes among patients with prostate cancer at the time of diagnosis and after definitive initial treatment. While there was a wide range of impact on risk reclassification reported across studies, there was no clear pattern in these changes across tests. We did find that there was no change in risk classification for a majority of patients apart from a potentially greater rate of reclassification among those at intermediate risk by clinical features. Despite the large proportion of patients without a change, across the identified studies there were still clinically meaningful proportions of included patients who experienced a change in risk assessment that could contribute to important changes in treatment. Of note, most of the data on risk reclassification have been generated with the Oncotype test and were almost exclusively related to risk assessment at the time of initial diagnosis. With respect to the clinical utility of these tests, we found that providers do change their treatment recommendations after receipt of test results in observational studies, although this was not found in the single randomized trial. Evidence around clinical utility was distinct by test type and timeframe such that Oncotype and Prolaris were studied only at initial diagnosis and Decipher only after prostatectomy. Last, we found that these tests do seem to provide additional prognostic information with respect to biochemical recurrence, development of metastatic disease, and prostate-cancer-specific mortality; we have the most certainty of this effect with Decipher compared to the other 2 tests. The value of that additional prognostic information is limited by these findings that largely stem from patients diagnosed and treated prior to the current era of prostate cancer management defined by advanced screening practices as well as evolution in pathologic assessment, staging, and treatment modalities. Of note, we did not find any evidence of acute harms of the tests studied, although there is likely limited harm as the test does not require new tissue acquisition and does not identify or disclose genetic risk applicable to patient family members.

While not specified in our KQs, an outcome of interest for the nominators of this topic was evidence related to the cost and economic value of genomic tests in the management of prostate cancer. Unfortunately, none of the identified studies reported cost-related outcomes. One recent systematic review on health economic evidence for both liquid and tissue-based molecular tests provides us with some cost-related information. Four of the 22 studies included by Degeling et al were relevant to the tests of concern in this review.^72^ They reported that 3 of the 4 studies found that these tests led to increased overall costs but concluded that they were cost effective when considering improved clinical outcomes; 1 study found cost savings for low-risk populations and increased costs among intermediate-risk patients. Lobo et al provide some guidance in this area using model simulation based on individualized decision analysis to estimate additional quality-adjusted life years (QALYs) based on genomic classifier test risk estimates in patients post-prostatectomy.^73^ Specifically, they found an additional 0.07 QALYs with use of genomic classifier testing.

## CERTAINTY OF EVIDENCE FOR KEY OUTCOMES

To provide context for the findings described in this report, we conducted certainty of evidence (COE) ratings for those outcomes with adequate volume and comparability of relevant studies. These ratings reflect the degree of confidence we have for the summary findings. We made our COE assessments by genomic classifier test type across the KQ3 outcomes of biochemical recurrence (BCR), metastases, and prostate-cancer-specific mortality (Table 14). Overall, we noted that while the effect estimates were consistent in showing a clinically relevant additive benefit of the genomic tests, our confidence assessments were frequently downgraded because most identified studies used older data that have limited relevance to modern clinical practice (indirectness).

For Decipher, we have low COE that this test provides additional prognostic information for risk of BCR, metastases, and prostate-cancer-specific mortality. For BCR, this determination was limited by ROB across the 4 relevant studies and imprecision of effect estimates. For metastases, while 15 observational studies contributed data to this effect estimate, our assessment was downgraded for ROB and serious indirectness, as much of the contributing patient data from the 1980s to 1990s reflect a different era of management standards. For prostate-cancer-specific mortality, our assessment of the findings from 5 studies was downgraded due to indirectness as noted for metastases and the imprecision of the effect estimate. Additional prospective studies with data drawn from current era of prostate cancer management could change this assessment.

For Oncotype, we have very low COE across all 3 outcomes. Indirectness due to temporal source of the data was noted for each outcome. In addition, for BCR, we downgraded for imprecision and inconsistency across the 3 relevant studies. For metastases and prostate-cancer-specific mortality, the same 3 studies contributed data, and we downgraded both of these outcomes for ROB and imprecision. Additional studies, especially prospective, conducted in the current management era would affect this assessment.

For Prolaris, we have very low COE across all 3 outcomes. Our assessment for all 3 outcomes was downgraded for ROB, indirectness, imprecision, and concerns for potential publication bias (BCR and metastases only). Of note, only 4 studies contributed relevant data. Additional studies, especially prospective studies conducted in the current management era would affect this assessment.

Table 14 Certainty of Evidence for Genomic Tests and Biochemical Recurrence, Metastasis, and Prostate-cancer-specific Mortality

Outcome | Number of Studies | Findings | Certainty of Evidence (Rational)
Decipher
Biochemical recurrence | 4 observational studies (525 patients) | HR range (0.32 to 1.36); AUC range clinical features (0.56, 0.64); AUC range clinical features and genomic test (0.69 to 0.85) | Low certainty; (Downgraded for serious risk of bias and serious imprecision)
Metastases | 15 observational studies (3,165 patients) | HR range (1.17 to 61.6); OR range (1.36, to 1.48); AUC range clinical features (0.46 to 0.88); AUC range clinical features and genomic test (0.67 to 0.89) | Low certainty; (Downgraded for serious risk of bias and serious indirectness)
Prostate-cancer-specific mortality | 5 observational studies (1,807 patients) | HR range (1.39 to 56.0); OR range (1.20); AUC range clinical features (0.55 to 0.81); AUC range clinical features and genomic test (0.71 to 0.78) | Low certainty; (Downgraded for serious indirectness and serious imprecision)
Oncotype
Biochemical recurrence | 3 observational studies (876 patients) | HR range (1.10 to 2.73); AUC range clinical features (0.59); AUC range clinical features and genomic test (0.68) | Very low certainty; (Downgraded for serious inconsistency, serious indirectness, and serious imprecision)
Metastases | 3 observational studies (793 patients) | HR range (2.24 to 2.63); AUC range clinical features (0.55 to 0.77); AUC range clinical features and genomic test (0.65 to 0.824) | Very low certainty; (Downgraded for serious risk of bias, serious indirectness, and serious imprecision)
Prostate-cancer-specific mortality | 3 observational studies (847 patients) | HR range (2.69, 2.30); AUC range clinical features (0.55 to 0.762); AUC range clinical features and genomic test (0.69 to 0.822) | Very low certainty; (Downgraded for serious risk of bias, serious indirectness, serious imprecision)
Prolaris
Biochemical recurrence | 9 observational studies (2,758 patients) | HR range (1.24 to 10.9); AUC range clinical features (0.542 to 0.78); AUC range clinical features and genomic test (0.65 to 0.86) | Very low certainty; (Downgraded for very serious risk of bias, serious indirectness, serious imprecision, and suspected publication bias)
Metastases | 4 observational studies (2,571 patients) | HR range (2.05 to 4.19); AUC range clinical features (0.55 to 0.894); AUC range clinical features and genomic test (0.90); Test only (0.73) | Very low certainty; (Downgraded for serious risk of bias, serious inconsistency, serious indirectness, and serious imprecision)
Prostate-cancer-specific mortality | 3 observational studies (1,989 patients) | HR range (1.65 to 2.57); AUC range clinical features (0.74, 0.55); AUC range clinical features and genomic test (0.78); AUC test only (0.66) | Very low certainty; (Downgraded for serious risk of bias, serious inconsistency, very serious indirectness, and serious imprecision)

Abbreviations. AUC=area under the curve; OR=odds ratio; HR=hazard ratio.

## CLINICAL AND POLICY IMPLICATIONS

Identifying patients who would benefit from treatment and tailoring the intensity of that treatment to an individual patient remains a major challenge for prostate cancer management despite multiple existing risk stratification tools. Previously developed risk stratification (or prognostic) tools utilize combinations of readily available clinical parameters including tumor grade, PSA level, and clinical stage to provide some assessment of individual patient prognosis; however, these tools have limited prognostic ability. The purpose of this review has been to determine whether 3 commercially available genomic classifiers can refine prognosis assessment and lead to more personalized management of patients with prostate cancer.

### KQ1

Among individuals with localized prostate cancer who are considering first-line definitive treatment, does genomic testing impact risk stratification? At present, the most commonly used clinical risk stratification incorporates clinical tumor stage, Gleason score or grade group classification, as well as serum PSA. The rationale for pursuing individualized tumor characterization through genomic classification testing is that it may further refine risk stratification. The majority of studies addressing KQ1 utilized the Oncotype genomic classifier, were retrospective in design, and most frequently utilized NCCN risk stratification as a comparator. For patients with very low to intermediate risk disease, more often than not, there was no significant change in risk stratification compared to the clinical classification scheme. In this patient population, genomic testing may only serve to potentially reassure these patients that active surveillance remains a reasonable option for them. Similarly, for those already treated with prostatectomy, most patients were classified into the same or lower risk classification between clinical risk factors and genomic classifier testing. For patients classified pre-treatment as intermediate risk, Oncotype testing could potentially reassure those who are averse to treatment that active surveillance remains a reasonable option. There were limited available data on change in risk stratification by race; however, what we did identify did not appear to be significantly influenced by race, providing some reassurance that these results appear applicable across different races.

### KQ2

How has genomic testing impacted the choice of treatment intensity to date? Across observational studies, when testing occurred at the time of diagnosis, there have been more frequent recommendations for active surveillance. This would be in line with the finding that most patients tend to be classified at similar or lower risk levels after genomic testing. However, in the single randomized trial evaluating the incorporation of Oncotype testing into treatment decisions, there was no statistically significant effect of receipt of testing on treatment choice. Although there was a tendency to recommend adjuvant therapy when patients were classified as higher risk by Decipher at the time of prostatectomy, there was no clear pattern of adjuvant treatment or surveillance after prostatectomy based on genomic classifier use. Because adjuvant therapies such as radiation with or without hormonal therapy can be associated with increased long-term side effects and appear equivalent in outcomes to early salvage radiation at the time of biochemical recurrence for a large portion of patients, further investigation into use in this setting to identify those at most need of additional therapy would seem warranted. We note that evidence of change in management after testing primarily reflects current practice patterns surrounding test use and is only helpful if occurring in the context of a test with evidence of acceptable predictive ability.

### KQ3

Finally, among individuals who have undergone definitive treatment for localized prostate cancer, can genomic testing of the pre-treatment biopsy or radical prostatectomy specimen refine prognosis in terms of biochemical recurrence-free survival, metastases-free survival, and prostate-cancer-specific mortality beyond clinical classification schemes? Overall, genomic classifiers showed meaningful additive value in prognostic ability beyond the previously available clinical models and by improvements in discriminatory characteristics.^74^ However, only 2 of the 39 studies included prospectively collected cohorts, and only 9 of the 39 studies included patients treated with definitive radiation therapy. In addition, patients in these studies were diagnosed and managed over several decades, while screening patterns, pathologic grading and biopsy methodology, radiological staging utilizing pelvic MRI, treatment recommendations and techniques, and follow-up of patients with prostate cancer have evolved significantly. Even more contemporary changes, including staging with PET imaging and artificial-intelligence-generated classification schemes, warrant consideration as the prognostic utility of genomic classifiers continues to be assessed. In addition, while these studies demonstrated improved prognostic ability of the genomic classifiers over clinical models, they were not designed to predict response to therapy, and therefore these findings are insufficient to guide intensification or de-escalation of treatment despite the demonstration of change in treatment intensity shown in KQ2.

## PRIOR SYSTEMATIC REVIEWS

### KQ1

Only 1 prior systematic review explicitly discussed any of the genomic classifiers of interest in reference to risk reclassification when compared to existing clinical risk models.^75^ Olleik et al reviewed 4 studies reporting reclassification with use of Decipher, 1 with Oncotype, and 3 with Prolaris, mostly in the post-radical prostatectomy setting. Six of the articles in the Olleik review were included in this report, and we additionally included 6 studies related to Oncotype. Estimates of frequency of reclassification as described by Olleik et al displayed a similar variability across studies but were not described by baseline risk classification as we have done.

### KQ2

Three recent systematic reviews evaluated the extent to which tissue-based genomic testing impacts the choice of treatment intensity.^75–77^ All published since 2017, these reviews include a total of 16 articles, all of which except 3 were eligible for our review. All 3 reviews used a formalized risk of bias tool to assess article quality. The 3 reviews included articles about Prolaris in low- and intermediate-risk localized prostate cancer and summarize these studies about change in treatment before and after Prolaris CCP results as ranging between 48% and 65%, including a portion where interventional treatment was reduced (37% to 72%) or increased (23% to 27%). Two reviews suggested similar findings (eg, a 21% to 24% decrease in interventional treatment). The Decipher test was examined in only 1 review (which included 4 studies about post-prostatectomy, all of which were included in our review), and authors summarized that the test’s clinical utility was reflected in a change of post-prostatectomy treatment recommendations in 31% to 51% of the time, with 16% to 42% changing from any to no treatment.^75^

Our report also includes a randomized trial from 2021, which, interestingly, found no change in treatment in men randomized to receipt of genomic testing with Oncotype during treatment decision-making. We also explored testing timing (post-initial biopsy and post-prostatectomy), more detailed treatment changes as a result of genomic testing, and treatment changes by race subgroups.

### KQ3

Six recent systematic reviews examined 1 or more of our 3 outcomes of interest^76,78–82^ relevant to the prognostic effect of tissue-based genomic tests after adjusting for existing prognostic clinical features following definitive treatment.

Two systematic reviews examined only the Decipher test.^80,82^ The remaining reviews included 17^79^ and 21^76^ studies about the utility of adding or incorporating genomic classifiers into clinical risk classification schemes to enhance prognostic accuracy across various disease outcomes. Our study improves upon this recent work, as we have included 39 studies, including the majority of the articles about all 3 genomic classifier tests from the last review,^76^ with an additional 12 articles from after 2019, beyond the end of the Fine et al search period.

In terms of substantive findings, each review has noted that genomic classifier tests have been able to improve on prediction of clinical outcomes compared to clinical features alone. For example, Jairath et al found a consistent independent association between the Decipher test results and various endpoints, including BCR, metastases, and prostate-cancer-specific mortality.^82^ For all 3 KQs, our review focused on Decipher, Oncotype, and Prolaris; however, some of the prior reviews included other tests, and few included all 3 tests. A few early reviews summarized the results of this rapidly changing field, but were not systematic reviews^81^ or did not include a formal risk of bias assessment.^78,81^

Overall, our findings are largely consistent with prior reviews in that these tests provide additive information to existing clinical risk stratification tools related to reclassification, may change the treatment plan or actual treatment for some prostate cancer patients, and better predict clinical outcomes. Our review adds to these prior reviews with a significantly increased number of studies, more recent studies, formal risk of bias assessment for all included studies, and exploration of test effects by key subgroups.

## LIMITATIONS

There are limitations to our review. While we developed an a priori protocol outlining populations of interest and a standardized approach to searching and evaluating the literature, we limited this evaluation to 3 commercially available genomic tests. Thus, our findings do not apply to other tests of genomic markers in the context of prostate cancer. In addition, we limited our search to publications after January 1, 2010, so any earlier publications related to the development of genomic tests of interest would not be captured.

We did not consider outcomes specific to the time of surgery such as adverse pathology, nor did we consider any literature related to use of these tests among patients with metastatic disease. Of note, there is ongoing investigation exploring the relationship between specific histologic distinctions, radiomics, and classification schemes derived by artificial intelligence in relation to prognosis; however, our review did not incorporate these burgeoning areas of scientific inquiry. We also note that there are current ongoing studies to assess the ability of genomic classifier tests in predicting response to treatment options, which was not within the scope of this review although at least 1 of the included studies reported some preliminary findings related to this question.^41^ In an attempt to capture the breadth of existing evidence, we included studies with notable aspects of heterogeneity, as noted below, which likely reduces our ability to identify a narrow effect estimate which could be applied to clinical practice. Finally, we were unable to compare across genomic test types as no identified literature provided a direct comparison.

### Publication Bias

Regarding the identified relevant literature, we consider important limitations by potential source of bias. Much of the identified literature for KQ3 was conducted as retrospective cohort studies from individual or grouped institutional data from previously treated patients; many of these were from the same institutions (as noted by multiple linked studies evaluating the same cohort data).^4,22,27,36,56,64,69,71^ Many of the included studies may overlap substantially, although in some cases, the amount of overlap is unclear.^52,57,59,61,63,77^ It is unknown if other institutions conducted retrospective analyses of their own patient populations, which may have had different practice patterns, including patterns in which different patients underwent genomics tests. In addition, many of the included studies were supported by the companies that developed one of the 3 genomic tests of interest. It is notable that the bulk of the outcomes data for KQ3 for the Oncotype and Prolaris tests were among earlier endpoints such as biochemical recurrence, while Decipher-based studies were the predominant test studied for data with later or “harder” outcomes such as prostate-cancer-specific mortality. If studies for the other 2 tests of interest have been conducted with longer-term outcomes, we were unable to identify them in the published literature. It is possible that studies of Oncotype and Prolaris with longer-term outcomes have not been completed yet. We note that there are 4 Prolaris studies registered in clinicaltrials.gov that appear to have completed data collection but are without peer-reviewed publications or posted results^83–85^ or were terminated due to poor enrollment.^86^

### Study Quality

There are notable concerns related to study quality of the identified literature. For KQ2, study designs used to determine the impact of genomic classifier testing on treatment recommendations were primarily observational, with case reviews in abstract from actual clinical care or provider self-report of care recommended before and after receiving test results; we found only 1 randomized trial addressing KQ2.

For KQ3, many studies were retrospective and could not control for practice patterns. In addition, many studies employed genomic classifier tests run on stored biopsy or prostatectomy tissue, some of which could be up to 30 years old at the time of analysis. Thus, rates of unusable specimens due to inadequate tissue sample were often substantial. It is suspected that older samples and those from patients with earlier or more favorable stage cancers, with lower cancer burden, may have been more likely to have samples inadequate for genomic testing, which could bias the results to find a greater relationship between test scores and worse prognosis. We considered a loss of 20% to 30% to be acceptable given the context for these studies^87^; loss of sample at higher levels was a common cause of downgrading for risk of bias. Follow-up among studies pertinent to KQ3 was limited (the majority was less than 10 years) relative to the natural history of prostate cancer. Additional common sources of bias across included studies was lack of clarity around how the sampled population in retrospective studies were identified and sampled and potential confounding due to factors driving which patients received the test.

### Heterogeneity

Potential sources of heterogeneity in effects include study design (eg, cohort, nested case-control, case-control), use of different clinical risk classification systems as comparators (eg, NCCN, CAPRA, AUA), different approaches to primary definitive treatment (eg, radical prostatectomy vs primary radiation therapy with or without hormonal treatment), and different definitions of the outcomes of interest (eg, various ways of measuring changes in treatment intensity, as well as biochemical recurrence). In addition, screening patterns have changed, and effective treatment options for prostate cancer have improved significantly over the last few decades; yet this literature draws from patient care provided between 1985 and 2019, which introduces significant heterogeneity. Screening patterns may also vary among the clinical settings where these patients were selected. In particular, while clinical risk prediction tools and genomic classifier tests use similar language for risk determination, different cut points are used and are based on different data input. There are other likely sources of heterogeneity that were not reported, such as potential differences in pathology practice patterns, potential differences in clinical practice patterns around the extent of procedures used to identify pathologic node presence (eg, was a lymph node dissection conducted), and the tendency of practitioners across institutions to order genomic tests at all and for specific types of patients during routine clinical practice. Lastly, the follow-up window described in the KQ3 studies varied and the long-term outcomes (ie, metastasis and PCSM) are rare events.

### Applicability to the VA Population

Several of the identified studies included Veterans^18,23,43,44,46,52,54,56,57,59,67,71^ diagnosed and/or treated within the VA health care system (VAHCS), and 1 study used Veteran-only data from the VAHCS. Across all included studies, the patient populations were reasonably similar based on patient characteristics (eg, age, comorbidities) to the Veteran population such that these findings are expected to be generalizable to the VA clinical setting. It is relevant that deployed Vietnam-era Veterans have potential exposure to Agent Orange, which is suspected to confer an increased risk of prostate cancer. While some patients included in non-VA-based cohorts may have had this exposure while not being identified as such, it is likely that this additional risk of a specific Veteran population is underappreciated based on our findings. Of note, 1 study included subgroup analyses by exposure to Agent Orange.^18^

## FUTURE RESEARCH

To inform future work in this area, we consider the PICOTs framework (Table 15). For studies addressing KQ1 or KQ3, prospective cohort studies with sufficient follow-up would be preferable study designs, while randomized trials would be preferred for KQ2.

Table 15 Evidence Gaps for Effects of Genomic Tests on Key Outcomes

PICOTS Domain | Evidence Gap/Area for Future Exploration
Population | - Veterans with known Agent Orange exposure; - Patients from historically marginalized populations; - Patients with family history of early-onset prostate cancer; - Patients with high risk germline mutations for prostate cancer
Intervention | - Indication for treatment of patients on active surveillance; - Oncotype/Prolaris in patients after definitive treatment; - Decipher in patients prior to definitive treatment; - Identifying candidates for focal therapy
Comparator | - Alternative genomic tests of interest for direct comparison; - Direct comparison between Decipher, Oncotype, Prolaris, or other genomic tests; - A broadly accepted test of core measures for adjustment in analyses, and/or 1 clinical risk classification system for each key clinical population
Outcomes | - Long-term outcomes such as prostate-cancer-specific mortality, overall mortality; - Harms (eg, overtreatment, undertreatment); - Cost
Timing | - Follow-up beyond 5 years, ideally up to 15 years

We also note that there was minimal evidence analyzing the effect of genomic testing for prostate cancer on outcomes of interest among subpopulations including historically minoritized racial/ethnic groups. Black men experience more aggressive prostate cancer and suffer a higher mortality rate compared to White men.^88^ It is important to recognize that race is a social construct and is not based on underlying genetics; however, ancestral genomic patterns of risk could be transferred through inherited genetics. Of note, recent findings suggest that race-based differences in prostate cancer outcomes are nullified by the receipt of standardized treatment and equal access to care.^89^ Future studies examining treatment intensification after genomic testing could stratify by race/ethnicity of patients to explore and identify discriminatory practice patterns (The article by Rayford et al gives an example of such an approach.^25^)

### Ongoing Work

To project forthcoming evidence from currently active studies in this area, we conducted a rapid review of clinical trials.gov to identify studies in active recruitment, those not yet recruiting, or those that were closed but which do not yet have evidence of related publications. We have listed the identified ongoing studies relevant to each KQ in Appendix F. Importantly, these all are prospective studies. Note that this list is not exhaustive, as observational studies are routinely not registered in clinical trials.gov, and it may not capture work in this area being conducted in other countries. There is also evidence of analyses in earlier stages of dissemination (eg, conference abstracts^90^) which, if published in a peer-reviewed publication, could be eligible for future systematic reviews. Finally, there have been at least 3 additional relevant manuscripts published and 1 released as a preprint since our search date^91–94^; of note, the results of these more recent articles are generally consistent with our findings.

## CONCLUSIONS

Genomic classifier tests offer the potential to improve prognostic assessment for patients with prostate cancer and to provide critical information for patient-provider deliberations on key management decisions. While there is some evidence elucidating when such tests may lead to a change in risk classification and how frequently providers are changing treatment recommendations based on test reports, the key data needed to inform the value of these genomic classifier tests lies with their ability to accurately predict risk of key long-term clinical outcomes that are relevant to patients. Definitive evidence of the prognostic ability of these tests is still needed from current management-era data. In the meantime, providers and their patients can take note that genomic classifier tests appear to provide some additional prognostic benefits that could offer value when treatment decisions are uncertain.