# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 1) summarizes the results of the study selection process (full list of excluded studies is in Appendix D).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

We identified 2,816 records through searches of MEDLINE (via Ovid), Embase, and Web of Science (see Figure 2). An additional 5 articles were identified through hand searching and reviewing bibliographies of relevant review articles for a total of 2,821 articles. After removing duplicates, there were 1,573 articles remaining in total. After applying inclusion and exclusion criteria to titles and abstracts, 145 articles remained for full-text review. Of these, 59 were included and retained for data abstraction. Of the 59 articles, 55 were identified as unique studies. They consisted of 1 randomized controlled trial, 1 secondary analysis of a randomized trial, 1 individual patient-level meta-analysis, 2 case-control studies, and 50 observational cohorts (8 prospective, 42 retrospective). The studies were conducted across North America, Europe, and Asia (United States, Britain, Finland, France, Germany, Italy, and China). Multiple studies had overlapping cohorts and it was not always possible to determine the exact degree of overlap. There were 4 studies conducted exclusively in the VA; however, 7 additional studies included a VA cohort.

Of the 55 studies, 11 related to KQ1, 15 to KQ2, and 39 to KQ3. Several studies had outcomes related to more than one KQ. For details of study characteristics, see Appendix E.

In the results section below for each KQ, we report results by genomic classifier test type in alphabetical order for consistency: Decipher, Oncotype, Prolaris.

## KEY QUESTION 1: AMONG INDIVIDUALS WITH LOCALIZED PROSTATE CANCER WHO ARE CONSIDERING FIRST-LINE DEFINITIVE TREATMENT, DOES THE ADDITION OF A TISSUE-BASED GENOMIC TEST TO EXISTING CLINICAL RISK MODELS IMPACT RISK CLASSIFICATION?

### Key Points

- The majority of identified studies (6 of 11) that evaluated risk reclassification used the Oncotype genomic classifier run on biopsy specimens prior to definitive treatment.
- Prior to definitive treatment, Oncotype results did not change the clinical risk level in 37% to 81% of patients, reclassified 3.2% to 44% of patients to a higher risk, and reclassified 12% to 35.4% of patients to a lower risk. For Decipher, 1 large study reported no change in classification in 24% of patients, a higher classification in 35%, and a lower classification in 41%. The 1 small study using Prolaris had no change in classification of 58% of participants, higher reclassification in 25%, and lower in 17%.
- Among baseline intermediate-risk patients, Oncotype led to a lower reclassification in 4% to 28.8% of cases, higher classification in 2% to 69%, and no change in classification in 15% to 96%.
- Few studies examined differences in risk reclassification among minoritized racial groups.

Overall, 11 studies reported risk reclassification from baseline risk assessment with clinical features to genomic classifier testing.^16–26^ Reclassification was reported either as a direct comparison of risk levels using the same risk labels or through integration of the genomic classifier test results into the clinical features risk assessment. One study reported risk reclassification among intervention arm patients in a randomized trial,^23^ 4 in prospective cohort studies,^19,20,24,26^ 5 in retrospective cohort studies,^16,17,21,22,25^ and 1 in an ambidirectional study (a retrospective and prospective cohort).^18^ Three studies used Decipher,^19,22,26^ 6 used Oncotype,^16–18,20,23,24^ and 2 used Prolaris.^21,25^ The majority of patients in these 11 studies fell into intermediate or lower baseline clinical risk classification, with only 3 studies including patients at high risk.^19,21,22^ Overall, among studies reporting time of data collection, the years over which the prospective studies were conducted ranged from 2012–2014, the retrospective studies drew data from years 2013–2020, and the ambidirectional study from 2013–2014 for the retrospective component and 2015–2016 for the prospective component. For clinical-based risk classification, 8 studies used NCCN criteria,^16–20,22–24^ 1 AUA,^25^ 1 EUA,^21^ and 1 CAPRA-S.^26^ Eight studies were found to have low ROB,^17–22,24,26^ 2 moderate ROB,^16,25^ and 2 high/serious ROB (designation term depending on instrument used).^18,23^ Common sources of ROB for articles relevant to this KQ included missing patient-level data due to inadequate or poor quality sample, lack of information about which patients were receiving the test, and inadequate control of confounders (Figures 2 and 3).

Figure 2 ROBINS-I Risk of Bias Assessment for KQ1 Studies

Notes. Some of these studies are included for both KQ1 and KQ2. ROB assessment may differ by outcome.

Figure 3 Risk of Bias Assessment for the Randomized Trial

Notes. Green plus denotes low risk of bias; red dash denotes high risk of bias; yellow question mark denotes some concerns about risk of bias.

### Risk Reclassification Among Patients Prior to Definitive Treatment

#### Decipher

We identified 2 studies that examined the change in risk classification following Decipher testing (Figure 4 and Table 2).^19,22^ One low ROB study^19^ included data from 2 prospective cohorts. The first cohort included 4,960 patients diagnosed between 2014 and 2016 with NCCN clinical risk classification ranging from low to very high and who had a Decipher test run on radical prostatectomy tissue. The second cohort included 977 patients diagnosed in 2016 with a similar range of NCCN clinical risk classification and who underwent Decipher testing on pretreatment biopsy tissue specimens. Reclassification results were similar across the 2 included cohorts comparing risk from the 4-tier NCCN risk groups (ie, low, favorable intermediate, unfavorable intermediate, high) to a 6-tier risk spectrum combining both clinical and genomic information, with 21% and 24% of cases without a classification change, 43% and 35% with a higher reclassification, and 36% and 41% with a lower reclassification. Of note, reclassification using a novel six-tier system that incorporated both NCCN risk and genomic risk found a greater proportion reclassified with no change in 33.3%, reclassification to a lower risk level in 27.7%, and to a higher level in 38.9%. A smaller low ROB retrospective study^22^ including 57 men with predominantly low or intermediate risk disease by clinical assessment found half of cases had no change in risk classification while 30% were reclassified to a lower risk and 14% higher.

#### Oncotype

Six studies^16–18,20,23,24^ with a total of 907 patients evaluated changes in risk classification after Oncotype genomic testing (Table 2). Identified studies included patients with NCCN classification of very low to intermediate risk. Overall, the median proportion without a change in risk classification was 69% (range from 37% to 81%), median percent reclassified to a higher risk was 6% (range from 3.2% to 44%), and median percent reclassified to a lower risk was 18 (range from 12% to 35.4%).

The 1 randomized trial^23^ examined change in risk among the 104 patients assigned to the intervention arm who had undergone Oncotype testing on biopsy specimens and who had baseline NCCN risk evenly distributed from very low to low intermediate risk (note that low intermediate was defined as favorable intermediate risk but excluding patients with Grade Group 2 and more than 3 positive scores and including patients with a PSA of 10–20 ng/mL if the PSA density was less than 0.15). Overall, in this study 40% of patients had no change in risk, 43% were reclassified as higher risk, and 17% were lower.

Two prospective studies evaluated Oncotype effect of risk reclassification, and each found that the majority of patients had no change in risk classification. First, a low ROB prospective study^24^ of 158 patients from 3 urologic practices with risk assessment before and after testing reported no change in 61.4% with 3.2% reclassified lower and 35.4% higher. Second, a low ROB study^20^ prospectively collected data on 258 newly diagnosed patients after institutional availability of genomic testing with Oncotype. The majority of patients (77.5%) had no change in risk classification while 5.8% were adjusted higher and 16.7% lower.

The other 3 Oncotype studies were retrospective. One study^17^ evaluated 134 patients at a single institution in a low ROB study and found that the majority of patients had no change in classification and more patients were reclassified to a lower risk than changed to a higher risk category. One small, moderate ROB, single-institution cohort study of 63 patients^16^ found 37% had no change in risk classification. Finally, 1 study^18^ evaluated risk reclassification among 190 newly diagnosed Veterans from 6 VA facilities after Oncotype testing became available and found that 81% had no change in risk classification while 7% were adjusted higher and 12% lower.

#### Prolaris

One low ROB study^21^ evaluated a small retrospective cohort study with 52 newly diagnosed patients from 2 academic hospitals who had Prolaris tests run on biopsy specimen (Table 2). Of this cohort with 29% of patients classified as high risk by European Association of Urology criteria, 58% were unchanged, 25% changed to a higher risk classification, and 17% lower.

Figure 4 Median Percent Reclassification by Genomic Classifier Test Type

Table 2 Change in Risk Classification with Genomic Classification Testing Among Men Prior to Definitive Treatment

Study; Total N; Design; Tissue Source | Clinical Characteristics Treatment; Median Test Value | Pre-test Risk Classification | No Change in Risk; N (%) | Reclassified Higher; N (%) | Reclassified Lower; N (%)
Decipher
Spratt, 2018^19^ ^a,b^; 4,960; Prospective cohort I; RP specimen | PSA <200; Stage T1c, T3b, clinical N0; Median GC: NR | NCCN:; Low: 203 (4.1%); Favorable int: 948 (19.1%); Unfavorable int: 634 (12.8%); High/very high: 3,145 (64.0%) | 21% | 43% | 36%
Spratt, 2018^19^ ^a,b^; 977; Prospective cohort II; Biopsy specimen | PSA <200; Stage T1c, T3b, clinical N0; Median GC: NR | NCCN:; Low: 315 (32.2); Favorable int: 198 (20.3); Unfavorable int: 284 (29.1); High/very high:180 (19.4) | 24% | 35% | 41%
Klein, 2016^22^ ^c^; 57; Retrospective, single institution; Biopsy specimen | PSA >20; Stage pT3 or positive margin or GG ≥8; All later underwent RP; Median GC: 0.38 (IQR 0.29 to 0.49) | NCCN:; Low: 23 (40.4%); Int: 27 (47.4%); High: 4 (7.0%); Unknown: 3 (5.3%) | 51% | 14% | 30%
Oncotype
Murphy, 2021^23^; 191 patients (104 intervention with test); ENACT; Randomized trial; Biopsy specimen | Newly diagnosed; mean GPS within NCCN groups: very low 5 26.9, low 5 27.2, low intermediate 5 32.4 | NCCN:; Very low: 40 (38.5%); Low: 36 (34.6%); Low-int: 28 (26.9%) | 40% | 43% | 17%
Lynch, 2018^18^; 190 tested patients; Comparative cohort before/after test availability, 6 VAMCs; Biopsy specimen | Newly diagnosed; Median GPS: 26.5 (range 0 to 61) | NCCN:; Very low: 42 (22%); Low: 81 (43%); Int: 67 (35%) | 81% | 7% | 12%
Seiden, 2021^16^; 63 men managed with AS; Retrospective, single Institution; Biopsy specimen | GG 6,7; Managed with AS; Median GPS 25 (IQR 19 to 4) | NCCN:; Very low: 7 (11%); Low: 24 (38%); Favorable int: 31 (49%); Unfavorable int: 1 (2%) | 37% | 44% | 19%
Eure, 2017^20^; 258 (posttest); Comparative cohort before (retrospective) and after (prospective) institutional testing; Biopsy specimen | Newly diagnosed; Median GPS: NR | NCCN:; Very low: 68 (26.4%); Low: 111 (43.0%); Int: 79 (30.6%) | 77.5% | 5.8% | 16.7%
Badani, 2015b^24^; 158, 3 urology practices; Prospective before and after test (own patients); Biopsy specimen | Newly diagnosed; Median GPS score: NR | NCCN:; Very low: 35 (22.2); Low: 71 (44.9); Low-int: 52 (32.9) | 61.4% | 3.2% | 35.4%
Gaffney, 2019^17^; 134; Retrospective, single institution; Biopsy specimen | All patients with GPS; GG 6 = 87 (65%); 7 = 47 (35%); 32 later underwent definitive treatment | NCCN:; Very low: 31 (23.1%); Low: 45 (33.6%); Int: 58 (43.3%) | 76% | 4% | 20%
Prolaris
Oderda, 2016^21^; 52; Retrospective cohort, 2 academic hospitals; Biopsy specimen | Newly diagnosed (All later underwent RP); Median CCP; −0.15 (−1.7 to 1.4) | EAU:; Low: 13 (25%); Int: 24 (46%); High: 15 (29%) | 58% | 25% | 17%

Notes.

a Spratt, 2018 included data for 2 separate cohorts

b Clinical data were pre-treatment

c Reclassification was unknown for 3 patients.

Abbreviations. CCP=cell cycle progression; EAU=European Association of Urology; GG=grade group; GPS=genomic prostate score; Int=intermediate; RP=radical prostatectomy.

### Subgroups of Interest

#### By Baseline Risk Category

Eight studies provided, to varying extents, risk reclassification rates stratified by clinical risk assessment (Table 3).^16–18,20,22–24,26^ No Prolaris studies included relevant subgroup analyses. In general, the majority of patients undergoing risk assessment with genomic classifier tests did not change risk levels; however, this appears to be more consistent among patients at very low risk based on clinical features.

Of the 5 studies that reported changes among patients with a baseline clinical risk classification of very low, all used Oncotype testing and NCCN criteria for risk classification.^17,18,20,23,24^ Sixty-six percent of patients identified to be at very low risk in the randomized trial remained at the same risk classification after testing,^23^ while the other 4 observational studies found 88% to 100% remained at very low risk with and without the test.

Eight studies reported changes in risk classification among patients at baseline low risk, 6 with Oncotype,^16–18,20,23,24^ and 2 with Decipher (3 cohorts total).^19,22^ Among the Oncotype studies, 38% to 70% of patients were not reclassified, 4.2% to 29% were reclassified to a higher risk category, and 20% to 57.7% were reclassified to a lower risk category. One Decipher-based study reported 2 cohorts, 1 using biopsy specimen (N = 4960) and 1 using prostatectomy tissue (N = 977)^19^; among baseline low-risk patients 25.7% and 19.7% remained the same, 25.7% and 12.8% were reclassified higher, and 57.1% and 67.5% lower. The Decipher-based study of 57 patients^22^ found 86.9% of patients were not reclassified, 13.1% reclassified as higher risk, and none were reclassified as lower risk.

The same 6 Oncotype-based studies reported reclassification among patients at baseline intermediate risk. Three studies^17,18,20^ (N = 895) found no change among 78% to 96% of patients, reclassification to a higher risk level among 0% to 2%, and reclassification to a lower risk level among 4% to 21%. Two studies reported changes among patients defined as low-intermediate risk (defined above) at baseline; 38% of the 104 patients at low-intermediate risk in the randomized trial^23^ reported no change. Twenty-nine percent of patients were reclassified to a higher risk level and 32% to lower risk level. The retrospective cohort^24^ found no change among 71.2% of 158 patients, 0% higher, and 28.8% lower. In this study, low intermediate risk was defined as favorable intermediate risk but with 3 or fewer positive cores (or 33% or fewer) if Gleason Grade Group 2. The small retrospective cohort of 63 patients^16^ reported that 65% of the 31 patients at baseline favorable intermediate risk were reclassified higher. The study with 2 cohorts reported changes across both favorable-intermediate and unfavorable-intermediate risk categories. For the favorable-intermediate group, 28.3% (biopsy cohort) and 21.0% (prostatectomy cohort) experienced no change, 27.3% and 22.3% higher, and 44.4% and 56.8% lower. For the unfavorable-intermediate individuals, 24.6% and 23.8% were not reclassified, 40.5% and 36.0% were higher, and 34.9% and 40.2% were lower. The other small Decipher-based study^22^ reported risk reclassification among baseline intermediate risk patients with 9 of 27 (33.3%) having no change, 18.5% reclassified higher, and 48.1% lower.

Only the Decipher-based studies reported risk reclassification among high-risk patients. The large study with both a radical prostatectomy and biopsy tissue cohort reported similar findings.^19^ Across both cohorts, 16.2% and 21.0% had no change in risk classification when incorporating genomic classifier risk scores, 64.4% and 51.85% higher (to a risk category of very high), and 19.4% and 27.2% lower. The 4 patients in the study by Klein et al^22^ who were classified as high risk at baseline were moved to a lower category.

Table 3 Reclassification by Baseline Clinical Risk Levels Prior to Definitive Treatment

Study; Total N; Design; Tissue Source | Clinical Characteristics Treatment; Median Test Value | Very Low | Low | Intermediate | High
Decipher
Spratt, 2018^19^ ^a^; 4,960; Prospective cohort I; Radical prostatectomy | PSA <200; Stage T1c, T3b, clinical N0; Median GC: NR | — | No change: 40/203 (19.7%); Higher: 26/203 (12.8%); Lower: 137/203 (67.5%) | Favorable Int; No change: 199/948 (21.0%); Higher: 211/948 (22.3%); Lower: 538/948 (56.8%); Unfavorable Int; No change: 151/634 (23.8%); Higher: 228/634 (36.0%); Lower: 255/634 (40.2%) | No change: 668/3175 (21.0%); Higher: 1644/3175 (51.8%); Lower: 863/3175 (27.2%)
Spratt, 2018^19^ ^a^; 977; Prospective cohort II; Biopsy specimen | PSA <200; Stage cT1c-T3bN0; Median GC: NR | — | No change: 81/315 (25.7%); Higher: 54/315 (17.1%); Lower: 180/315 (57.1%) | Favorable Int; No change: 56/198 (28.3%); Higher: 54/198 (27.3%); Lower: 88/198 (44.4%); Unfavorable Int; No change: 70/284 (24.6%); Higher: 115/284 (40.5%); Lower: 99/284 (34.9%) | No change: 29/180 (16.1%); Higher: 116/180 (64.4%); Lower: 35/180 (19.4%)
Klein, 2016^22^; 57; Retrospective, single institution; Biopsy specimen | PSA >20; Stage pT3 or positive margin or GG ≥8; All later underwent RP; Median GC: 0.38 (IQR 0.29 to 0.49) | — | No change: 20 (86.9%); Higher: 3 (13.1%); Lower: none | No change: 9 (33.3%); Higher: 5 (18.5%); Lower: 13 (48.1%) | No change: 0; Higher: 0; Lower: 4 (100%)
Oncotype
Murphy, 2021^23^; 191 patients (104 intervention with test); ENACT; Randomized trial; Biopsy specimen | Newly diagnosed; Median GPS: NR | No change: 19/29 (66%); Higher: 10 (34%); Lower: NA | No change: 13 (38%); Higher: 10 (29%); Lower: 11 (32%) | Low-Int; No change: 4 (15%); Higher: 18 (69%); Lower: 4 (15%) | —
Lynch, 2018^18^; 190 tested patients; Comparative cohort before/after test availability, 6 VAMCs; Biopsy specimen | Newly diagnosed; Median GPS: 26.5 (range 0 to 61) | No change: 37 (88%); Higher: 5 (12%); Lower: N/A | No change: 57 (70%); Higher: 8 (10%); Lower: 16 (20%) | No change: 59 (88%); Higher: 0; Lower: 8 (12%) | —
Seiden, 2021^16^; 63 men managed with AS; Retrospective, single Institution; Biopsy specimen | GG 6,7; Managed with AS; Median GPS: 25 (IQR 19 to 4) | — | Higher: 7/24 (29%) | Fav–Int; Higher: 20/31 (65%) | —
Eure, 2017^20^; 258 (post test); Comparative cohort before (retrospective) and after (prospective) institutional testing; Biopsy specimen | Newly diagnosed; Median GPS: NR | No change: 61 (90%); Higher: 7 (10%); Lower: NA | No change: 63 (57%); Higher: 8 (7%); Lower: 40 (36%) | No change: 76 (96%); Higher: 0; Lower: 3 (4%) | —
Badani, 2015b^24^; 158, 3 urology practices; Prospective before and after test (own patients); Biopsy specimen | Newly diagnosed; Median GPS: NR | N = 35; No change: 33 (94.3%); Higher: 2 (5.7%); Lower: NA | N = 71; No change: 27 (38.0%); Higher: 3 (4.2%); Lower: 41 (57.7%) | Low-int, N = 52; No change: 37 (71.2%); Higher: 0; Lower: 15 (28.8%) | —
Gaffney, 2019^17^; 134; Retrospective, single institution; Biopsy specimen | All patients with GPS; GG 6 = 87 (65%); 7 = 47 (35%); 32 later underwent definitive treatment | No change: 31/31 (100%) | No change: 26/45 (58%); Higher: 4/45 (9%); Lower: 15/45 (33%) | No change: 45/58 (78%); Higher: 1/58 (2%); Lower: 12/58 (21%) | —
Prolaris (No Studies)

Notes.

a Spratt, 2018, included data for 2 separate cohorts.

Abbreviations. AS=active surveillance; Fav=favorable; GG=grade group; GPS=genomic prostate score; Int=intermediate; IQR=interquartile range; PSA=prostate-specific antigen.

#### By Race

Three studies included a focus on the effect of genomic testing on risk reclassification among a historically minoritized population, specifically Black men. A randomized trial that included a majority of Black men (140 of 200 participants or 70%) did not report reclassification by race after Oncotype testing.^23^ A second moderate ROB study from a single-community urologic oncology practice^25^ compared the impact of Prolaris test results on risk classification between 150 Black and 60 White men with prostate cancer. Overall, there was no change in risk for 43% of Black men compared with 40% of White men, while 33% of Black men were reassigned to a lower risk and 24% higher compared with 50% lower and 10% higher for White men. Finally, a retrospective, single-institution cohort study^16^ included 63 participants (all Black) (results in Table 3) and found 37% without a change in risk, 44% higher, and 19% lower after Oncotype testing.

### Risk Reclassification Among Patients at the Time of Prostatectomy

One low ROB study (PRO-ACT)^26^ assessed the impact of Decipher on community-based urologist adjuvant treatment decisions among high risk patients after radical prostatectomy, but also noted that among those tested, 65.4% CAPRA-S intermediate patients were reclassified to a low-risk level. No other studies evaluated the effect of the genomic classifier tests of interest on risk reclassification after prostatectomy.

## KEY QUESTION 2: DOES TISSUE-BASED GENOMIC TESTING IMPACT THE CHOICE OF TREATMENT INTENSITY OR HARMS AMONG A) INDIVIDUALS WITH LOCALIZED PROSTATE CANCER BEFORE FIRST-LINE DEFINITIVE TREATMENT OR B) INDIVIDUALS WHO HAVE UNDERGONE RADICAL PROSTATECTOMY?

### Key Points

- Across 14 observational studies at the time of diagnosis and after prostatectomy, there was a pattern of changes to treatment recommendations after receipt of genomic classifier tests. The only available randomized trial, which incorporated Oncotype test results into treatment decisions, found no evidence of altered choice of treatment after receipt of the test.
- The impact of Oncotype or Prolaris results on treatment recommendations was evaluated only prior to first-line definitive treatment, while Decipher was used only evaluated after prostatectomy.
- Across the observational studies, rates of recommending active surveillance after an initial diagnosis were higher with genomic classifier use, though there was no clear pattern of adjuvant treatment or surveillance after prostatectomy based on test use.
- There was no clear pattern of treatment recommendations at the time of diagnosis attributable to genomic classifier testing.
- Patients classified as higher risk by Decipher at the time of prostatectomy were less likely to receive a recommendation of surveillance.
- Significant limitations of the evidence were that many patients were diagnosed and treated prior to the current era of prostate cancer management, and harms due to genomic classifier testing were not reported by any study.

Fifteen studies addressed the clinical utility, or impact of genomic classifier tests, on treatment intensity recommended and/or received: 5 for Decipher,^26–30^ 7 for Oncotype,^17,18,20,23,24,31,32^ and 3 for Prolaris.^33–35^ For Decipher-based studies, all considered treatment intensity after prostatectomy. For Oncotype- and Prolaris-based studies, treatment intensity determination was after biopsy and prior to first-line definitive treatment. Study designs addressing this key question included retrospective examinations of documented treatment recommendations before and after receipt of test results, prospective collection of provider recommendations before and after test results, and deidentified case reviews by providers with and without test results. For each specific genomic classifier test, at least 1 study considered treatment recommendations within risk-based subgroups. Two studies^17,22^ reported subgroup analysis by race/ethnicity, both of which used Oncotype.^18,23^ Of note, outcomes for impact on treatment are reported in multiple ways across studies, including overall change, increase/decrease in treatment recommendation, and change in specific treatment recommended (eg, active surveillance). The specific definition for treatment intensity varied by study such that some focused any interventional treatment versus observation^26,29,30,33,34^ and others employed a more nuanced approach to treatment.^18,24,35^ Across this group of 15 studies, 1 was found to have low ROB,^29^ 8 moderate ROB,^17,18,20,27,28,31,33,35^ 5 high/serious ROB,^23,24,26,32,34^ and 1 critical ROB.^30^ Common sources of potential bias include selection bias from providers choosing to order the test for included patients, reporting bias, outcome measurement approach, and missing data (Figure 5). Results for studies addressing this key question are listed in Table 4.

Next, we describe findings by tests used in the pre-definitive treatment setting followed by post-prostatectomy according to classifier test.

Figure 5 ROBINS-I Risk of Bias Assessment KQ2 Studies

Notes. Some of these studies are included for both KQ1 and KQ2. ROB assessment may differ by outcome.

### Overall Treatment Recommendations

#### Pre-definitive First-line Treatment

##### Decipher

No studies evaluated the impact of Decipher test use on first-line treatment decisions.

##### Oncotype

Two studies evaluated the effect of the Oncotype genomic classifier test on newly diagnosed patients with very low to intermediate risk disease based on the NCCN classification.^18,24^ First, a prospective study^24^ enrolled 158 newly diagnosed men from 3 clinical sites and collected urologist treatment recommendations before and after receiving of Oncotype test results. Overall, 26% of patients received a change of treatment recommendation after receipt of test results, with 16% of a lower intensity and 9% of a higher intensity, while 75% of treatment recommendations were unchanged. A second study with moderate ROB^18^ compared patient management strategies across 6 VA medical centers among a retrospective cohort of 200 patients treated prior to the introduction of Oncotype testing and a separate prospective cohort of 190 patients with similar prostate cancer who agreed to undergo genomic classification testing. Among patients who received Oncotype test results, 16% received any change in treatment recommendation, with 4% and 12% receiving a decreased and increased treatment intensity recommendation, respectively (Table 4).

##### Prolaris

Three studies reported on the impact of the Prolaris genomic classifier tests on overall treatment recommendations^33–35^: 2 prospectively evaluated provider recommendations before and after receipt of test results,^34,35^ and 1 compared cohorts of patients before and after the test became available as part of routine practice.^33^ In a large, prospective registry (PROCEDE-1000)^35^ of 1,206 patients with newly diagnosed prostate cancer whose providers (N = 124 from 21 states) completed 4 sequential questionnaires up to 6 months after ordering the test, nearly half of patients (95% CI [45.0, 50.6]) received a different treatment after Prolaris testing compared with the documented pre-test treatment recommendation. Of those who received a different treatment than initially recommended, 72.1% were a decrease in intensity versus 26.9% that increased. In addition, 17.6% of patients (213 of 1,206) experienced a change in treatment modality between non-interventional to interventional. The second prospective study^34^ enrolled 305 patients at the time Prolaris was ordered on biopsy specimens and compared treatment recommendations at the time of test ordering to recommendations reported after test results were received. Overall, in a majority of cases providers reported a change in treatment recommendation from before to after receiving Prolaris test results (64.9%, 95% CI [59.4, 70.1%]), with 40% receiving a decreased treatment intensity recommendation and 24.9% an increased intensity recommendation. Finally, a retrospective study evaluated treatment recommendations for 150 men from a single urologic practice before and after the institutional availability of routine Prolaris testing.^33^ Among men with Gleason 6 or 7 newly diagnosed prostate cancer, every unit increase in CCP score (Prolaris) had a greater odds of selecting definitive treatment than active surveillance (OR = 2.09, 95% CI [1.16, 3.94]); in comparison, each unit increase in CAPRA score had OR = 1.29, 95% CI [1.01, 1.66]).

Table 4 Impact on Overall Treatment Intensity by Genomic Classifier Test: Pre-definitive Treatment

Study; Setting; Total N; Design | Population; Clinical Characteristics | Any Change in Recommendations; Pre- to Post-test | [image] | [image] | [image] | Other | Impact on Treatment; Recommendation Change (OR, 95% CI)
Decipher (No Studies)
Oncotype
Lynch, 2018^18^; 6 VAMCs; 190 tested patients; Comparative cohort before-after test availability | Newly diagnosed; NCCN very low, low, and intermediate risk; Median GPS: 26.5 (range: 0 to 61) | 16% | 4% | 84% | 12% | — | —
Badani, 2015b^24^; 1 academic and 2 community-based urology practices; 158 patients ^a^; Prospective pre-post treatment recommendation | Newly diagnosed; NCCN very low, low, and intermediate risk; Median GPS: 21 (IQR 13 to 32) | 25% | 15.8% | 75.3% | 8.8% | — | —
Prolaris
Shore, 2016^35^; 21 states; 1206 patients; 124 providers; Prospective registry before/after test | Newly diagnosed; Stage T1c: 72.1%; Mean CCP:; −0.7 (range −2.8 to 2.0) | 47.8%; (95% CI [45.0, 50.6) | Of those with change: 72.1% | — | Of those with change: 26.9% | — | OR = 1.027 change in treatment per 1 unit increase CCP score
Crawford, 2014^34^; US-based practices; 305 patients; Prospective pre/post-test result | New diagnosis; AUA risk:; Low: 44.3%; Inter: 42.9%; High: 12.8%; Median CCP:; −0.71 (SD 0.83) | 64.9%; (95% CI [59.4%, 70.1%]) | 40% | 35.1% | 24.9% | — | —
Morris, 2021^33^; 150; Retrospective comparative cohort before/after initiation testing protocol | New diagnosis; Gleason on biopsy 6 or 7; Median CCP:; −0.5 (IQR −0.9 to 0.0) | — | — | — | — | — | OR = 2.08 (1.16 to 3.94) per unit increase CCP score

Notes.

a 175 enrolled, but 158 with evaluable data.

Abbreviations. CCP=cell cycle progression; IQR=interquartile range.

#### Post-prostatectomy

##### Decipher

Five studies (6 publications) were identified that addressed the impact of the Decipher genomic classifier test on treatment recommendations after prostatectomy (Table 5).^26–30,36^ Two prospective studies (3 publications) evaluated the impact of Decipher genomic classifier test results on treatment recommendations before and after receipt of test results among providers in the context of treating their own patients.^26,27,36^ Two articles^27,36^ published results on analyses from the moderate ROB PRO-IMPACT Trial. PRO-IMPACT was a prospective study across 19 sites that evaluated treatment recommendations at the time the Decipher test was ordered versus after the results were received and then again 12 months after enrollment.^27,36^ Among 242 patients eligible for either ART (non-organ-confined disease) or SRT (PSA ≥0.2 ng/ml post radical prostatectomy), treatment recommendations changed after Decipher testing for 17% and 30% of patients in the ART and SRT cohorts, respectively. Patients categorized as high risk had significantly greater odds of receiving ART at 12 months follow-up (OR = 2.99, 95% CI [1.3, 6.9]) and similarly higher odds of SRT (OR = 3.13, 95% CI [1.4, 7.1]) compared with patients categorized as not-high risk. Michalopoulos et al (PRO-ACT) similarly recruited 15 community-based urologists to provide treatment recommendations with and without Decipher results in the context of caring for patients after radical prostatectomy and who were eligible for adjuvant therapy.^26^ In this serious ROB study, physician participants submitted a median of 6 patient tests. In approximately one-third of cases (30.8, 95% CI [23%, 39%]), urologists changed their treatment recommendation after Decipher test results were reviewed. This was also measured as the odds of a change in treatment recommendation with a Decipher test (OR = 4.04, 95% CI [2.36, 6.92]).

Three studies asked practicing radiation oncologists and/or urologists to provide treatment recommendations based on deidentified patient cases with and without GC test results.^28–30^ The ASSESS-D study recruited 51 urologists from the AUA directory and had them review treatment plans with and without Decipher test results for 110 case histories from patients post radical prostatectomy who had an undetectable PSA (10 per urologist).^29^ Thirty-one percent of case reviews had a change in treatment recommendation after genomic classifier test results. Those with a high genomic classifier score (vs low) had a significantly higher odds of experiencing a change in treatment recommendation (OR = 8.57, 95% CI [5.27, 14.26]). Nguyen et al evaluated differences in the impact of a genomic classifier test on post-prostatectomy adjuvant treatment recommendations between urologists and radiation oncologists in a moderate ROB study.^28^ Decipher test results led to a change in treatment recommendations 35% of the time for radiation oncologists and 45% for urologists. Patients with high-risk Decipher results cared for by radiation oncologists had a significantly higher odds of any change in treatment recommendation than unchanged recommendations before to after testing (OR = 4.17, 95% CI [2.26, 7.70]); in comparison, urologist recommendations for patients with high-risk Decipher results had an even higher odds of any change in treatment recommendation (OR = 6.51, 95% CI [4.29, 9.88]). Finally, in a study at high ROB, the DECIDE study group^30^ asked 21 urologists to give treatment recommendations after reviewing pathology reports with and without genomic classifier test results from deidentified high-risk, post-radical prostatectomy (RP) cases. Twelve cases involved patients undergoing consideration for adjuvant treatment and 12 for salvage treatment (each case was reviewed by multiple physicians). Overall, 43% (95% CI [37%, 49%]) of ART case reviews experienced a change in treatment recommendation, with the Decipher test results with 27% (95% CI [19%, 35%]) having a decrease and 37% (95% CI [28%, 46%]) experiencing an increase in treatment intensification. Among SRT case reviews, 53% experienced changes in recommendations (95% CI [45%, 60%]) with 16% (95% CI [11%, 23%]) decreasing intensity and 61% increasing treatment intensity (95% CI [42%, 78%]).

##### Oncotype

No studies evaluated the impact of Oncotype test use on post-prostatectomy treatment decisions.

##### Prolaris

No studies evaluated the impact of Prolaris test use on post-prostatectomy treatment decisions.

Table 5 Impact on Overall Treatment Intensity by Genomic Classifier Test: Post-prostatectomy

Study; Total N; Design | Patient Characteristics | Impact on Treatment Decision | Other Outcomes
Decipher
Gore, 2017^36^; PRO-IMPACT study (X results); 19 sites; 265 patients; Prospective before-after test (own patients) | Post radical prostatectomy; non-organ confined prostate cancer or positive surgical margins (ART); or PSA increase or BCR ^a^ (SRT); Median GC score:; ART group: 6.2% (IQR 0.5 to 44.2); SRT group: 6.5% (IQR 0.5 to 62.8) | Overall changes in treatment decisions after test results:; ART: 27/150; 18% (95% CI [12%, 25%]); SRT: 37/115; 32% (95% CI [24%, 42%]) | Odds decision to pursue ART/SRT after test results per 5% increase in GC score:; ART: OR = 1.48 (95% CI [1.19, 1.85]; p < 0.001); SRT: OR = 1.30 (98% CI [1.03, 1.65]; p = 0.03)
Gore, 2020^27^; PRO-IMPACT study; 12-month follow up; 19 sites; 246 patients; Prospective before-after test (own patients) | Post radical prostatectomy; non-organ confined prostate cancer or positive surgical margins (ART); or PSA increase or BCR ^a^ (SRT); Median GC score:; ART group: 6.2% (IQR 0.5 to 44.2); SRT group: 6.5% (IQR 0.5 to 62.8) | Change from recommended pre-test to treatment administered at 12 months:; ART: 31/140; 22% (95% CI [16%, 30%]); SRT: 25/106; 24% (95% CI [16%, 33%]) | ART; Treatment decision change with GC score high vs not-high risk: OR = 9.75 (95% CI [3.3, 28.0]; p < 0.001); Before test to 12 months follow-up (treatment received): OR = 2.99 (95% CI [1.3, 6.9]; p = 0.01); SRT; treatment decision change with GC score high vs not-high risk: OR = 8.02 (95% CI [2.9, 22]; p < 0.001); Before test to 12 months follow up (treatment received); OR = 3.13 (95% CI [1.4, 7.1]; p = 0.006)
Michalopoulos, 2014^26^; 2014; PRO-ACT study; 15 urologists; 146 patients; Prospective before-after test (own patients) | Post radical prostatectomy with T3 disease or positive SM; Median GC 4.2%; (range 1.3% to 41.5%) | Change from treatment recommended before to after GC results:; 30.8% (95% CI [23%, 89%]); Any treatment to observation: 42.5% (95% CI [27%, 59%]); Observation to any treatment: 17.6% (11% to 26%) | Influence on treatment decision-making per 5 unit increase in GC score:; OR = 4.04 (95% CI [2.36, 6.92]; p < 0.0001)
Badani, 2015a^29^; 110 cases; 51 urologists; Deidentified case history review with and without test | Post radical prostatectomy with undetectable PSA; Median GC 3.85 (min, max: 1.2, 33.4); % reclassified: NR | Change from treatment recommended before to after GC results:; 31% (95% CI [27%, 35%]); Change from any treatment to observation:; 38% (95% CI [32%, 45%]); Change from observation to any treatment:; 16% (95% CI [12%, 20%]) | Impact on treatment decision-making MVA with GC score low vs high:; OR = 8.57 (95% CI [5.27, 14.26]; p < 0.001)
Badani, 2013^30^; 12 patient cases (ART); 12 patient cases (SRT); 21 urologists from 18 sites; Deidentified case history review with and without test | Post radical prostatectomy with adverse pathology; Median GC: NR | Change from treatment recommended before to after GC results:; ART: 43% (95% CI [37%, 49%]); SRT: 53% (95% CI [45%, 60%]) | Change from treatment to observation (decrease):; ART: 27% (95% CI [19%, 35%]); SRT: 16% (95% CI [11%, 23%]); Change from observation to treatment (increase):; ART: 37% (95% CI [28%, 46%]); SRT: 61% (95% CI [42%, 78%])
Nguyen, 2015^28^; 11 patient cases; 26 radiation oncologists | Post prostatectomy | Change from treatment recommended before to after GC results:; Radiation oncologists: 35% | Impact on treatment recommendations MVA with GC high vs not high):; Radiation oncologists; OR = 4.17; (95% CI [2.26, 7.70])
20 urologists; Deidentified case history review with and without test | D’Amico risk (n):; 2 – Low; 4 – Intermediate; 5 – High; Median GC: NR | Urologists: 45% | Urologists:; OR = 6.51; (95% CI [4.29, 9.88]
Oncotype (No Studies)
Prolaris (No Studies)

Notes.

a BCR defined as PSA ≥0.2 ng/ml with a confirmatory reading.

Abbreviations. ART=adjuvant radiotherapy; GC=genomic classifier; MVA=Multivariate Analysis; OR=odds ratio; SRT=salvage radiotherapy.

### Specific Treatment Choice

#### Pre-definitive Treatment

##### Decipher

No studies evaluated the impact of Decipher test results on specific treatment choice among patients prior to first-line definitive treatment.

##### Oncotype

We identified 6 studies (total 10,338 patients), including 1 randomized trial,^23^ 1 prospective before-and-after receipt of test study,^24^ and 4 retrospective or combination retrospective/prospective comparative cohort studies (Table 6).^18,20,31,32^ All studies examined the occurrence of active surveillance among men with newly diagnosed prostate cancer who had intermediate or low-risk disease. In all the observational studies, rates of active surveillance were higher among those patients who had received oncotype test results; however, in the 1 trial, the rate of active surveillance was lower in the study arm that received the oncotype test results.

The only randomized trial (Engaging Newly Diagnosed Men about Cancer treatment options, ENACT)^23^ evaluated the impact of receiving genomic testing on treatment decisions; specifically, 200 patients across 3 institutions (including 1 VA) with newly diagnosed NCCN very low- to intermediate-risk prostate cancer were randomized to receive standard counseling with or without the results of Oncotype genomic testing and were then evaluated the effect on uptake of AS. Eighty-eight percent of patients in the arm without the Oncotype test were recommended to receive active surveillance at the second treatment visits compared to 77% in the arm that did receive the Oncotype test. Overall, the intention-to-treat analysis of the initial choice of treatment (AS, surgery or radiation, undecided) found no significant difference between groups (p = 0.067), though there was a lower odds of AS use with testing though likely underpowered (OR = 0.49; 95% CI [0.22, 1.09]). Of note, 38 (43%) participants who underwent Oncotype testing were moved to a higher-risk group and 15 (17%) were moved to a lower-risk group.

One Oncotype-based prospective study enrolled 158 newly diagnosed men from 3 clinical sites with NCCN very low-, low-, or low-intermediate-risk prostate cancer and collected urologist treatment recommendations before and after receiving test results.^24^ They reported a 24% relative increase in AS recommendations after review of test results from 41% to 51%. Twenty-four of 38 patients with risk reclassification with Oncotype result had a change in treatment recommendation, all concordant with Oncotype test results. Another observational study reported a pre-specified interim analysis comparing treatment recommendation patterns before (retrospective by chart review) and after the introduction of genomic classifier testing (prospective) with Oncotype at multiple U.S. community-based urology practices.^20^ Across all risk categories, more patients were managed with AS in the tested group (74%) versus the untested group (62%), while persistence of AS at 1 year was 55% among those who were tested versus 34% who had not undergone testing (relative difference = 62%). A large retrospective cohort study used the Optum research database to identify 8920 men with low-risk cancer and reviewed their electronic medical records and administrative claims data from 2013 to 2016.^31^ They considered the role of Oncotype testing and/or MRI imaging (for our purposes, we only considered those who had undergone Oncotype testing [N = 300] versus those who had neither testing nor MRI [N = 7446]). Of those who had undergone testing with Oncotype at 6 months, 89% had no observed therapy (labeled as AS) versus 84% at 12 months; in comparison, at 6 months those without testing or MRI only 60% had no observed therapy versus 56% at 12 months. Overall, patients who had Oncotype testing had a 31.2% higher occurrence of no observed therapy than those without (95% CI [22.6, 39.7]). A VA-based study compared retrospective data on patient management strategies among 200 patients from 6 medical centers treated prior to the introduction of Oncotype testing to a prospective cohort of 190 patients who agreed to undergo genomic classification testing.^18^ Sixty-two percent of untested patients and 74% of tested patients were on active surveillance at 6 months (12% absolute difference; 19% relative difference). Of note, 26 of patients who received Oncotype testing had known Agent Orange exposure. Finally, a retrospective cohort study in which 15 urologists who had ordered at least 4 Oncotype tests provided data on 87 patients previously treated without genomic testing and 124 patients with Oncotype testing, all of whom had either Gleason score 3+3 or low volume 3+4 disease.^32^ They reported an absolute increase of 11% in the use of AS with patients who received Oncotype testing versus those who did not (61 vs 50%; p =0.110) and a similar difference in AS received (67% vs 43%).

##### Prolaris

No tests evaluated the impact of Prolaris test results on specific treatment choice among patients prior to first-line definitive treatment.

Table 6 Impact on Active Surveillance Use by Genomic Classifier Test

Study; Total N; Design | Patient Characteristics | Active Surveillance: Without Test | Active Surveillance: With Test | Other Outcomes
Decipher (No Studies)
Oncotype
Murphy, 2021^23^; ENACT study; 191 patients; Randomized trial | Newly diagnosed; NCCN favorable intermediate or below; Median GPS score: NR | At 2^nd^ treatment visit:; 88% | At 2^nd^ treatment visit:; 77% | Odds of choosing AS with test vs without:; OR = 0.49 (95% CI [0.22, 1.09])
Badani, 2015^24^; 158 patients; 3 clinical sites; Prospective before-after test (own patients) | Newly diagnosed; NCCN low-intermediate or lower; Median GPS: 21 (IQR range: 13, 32); 38 patients (24%) with risk reclassification post-GPS | At time test ordered:; 41% | After receipt of test results:; 51% | —
Eure, 2017^20^; 247 (before); 258 (after); Comparative cohort before (retrospective) and after (prospective) institutional testing | Newly diagnosed; NCCN intermediate or lower; Median GPS: NR; 23% pts had risk reclassification | 40% | 62% | AS persistence at 1 year:; With GPS test: 89%; Without GPS test: 86%
Lynch, 2018^18^; 200 (2013–2014); 190 (2015–2016); 6 VA HCS; Retrospective cohorts before and after institutional testing | Newly diagnosed; NCCN intermediate risk or lower; Median GPS (tested): 26.5 (range 0–61); Risk reclassification:; Lower: 12%; Higher: 7% | At 6 months:; 62% | At 6 months:; 74% | —
Canfield, 2017^31^; 300 GPS only; 7446 no GPS/MRI; Retrospective, comparative cohort before-after testing availability | Newly diagnosed; AUA low risk; Median GPS: NR; Reclassification: NR | No observed therapy; At 6 months: 60%; At 12 months: 56% | No observed therapy; At 6 months: 89%; At 12 months: 84% | At 6 months – 31% higher use of no observed therapy among tested than non-tested (22.6, 39.7; p<0.001)
Dall’Era, 2015^32^; 87 without testing; 124 with testing; 15 urologists; Retrospective | Newly diagnosed; NCCN Intermediate risk or lower; Median GPS: NR; % reclassification: NR | Recommended ^a^:; 30/60 = 50%; Received:; 43% | Recommended:; 69/114 = 61%; Received:; 67% | Absolute increase in recommended AS: 11%; Relative increase in AS recommendation: 22%; Absolute increase in AS received: 14%; Relative increase in AS received: 56%
Prolaris (No Studies)

Notes.

a Active surveillance (AS) defined as “active surveillance” or “watchful waiting” as noted in patient’s medical record.

#### Post-radical Prostatectomy

##### Decipher

Two studies (3 publications) evaluated the impact of Decipher test results on specific treatment recommendations (Table 7).^27,29,36^ As noted above, Gore et al published 2 studies from 1 trial that enrolled patients who were eligible for both ART and SRT.^27,36^ They found that 88.7% of the ART patients were recommended to have observation before Decipher test results compared to 79% after and from 60% to 51% SRT patients recommended for observation with Decipher test results. The second study found the same percentage receiving a recommendation for observation before to after test results were received, although, as noted above, an overall change in treatment recommendations of 30.8%.^29^ Of note, 42.5% who were initially recommended to receive ART were changed to observation.

Table 7 Impact on Observation After Prostatectomy by Genomic Classifier Test

Study; Total N; Design | Clinical Characteristics | Before Test Results | After Test Results
Decipher
Gore, 2017^36^; PRO-IMPACT; 19 sites; 265 patients; Prospective before-after test (own patients) | Post radical prostatectomy; non-organ confined prostate cancer or positive surgical margins (ART); or PSA increase or BCR ^a^ (SRT); Median GC score:; ART group: 6.2% (IQR 0.5 to 44.2); SRT group: 6.5% (IQR 0.5 to 62.8) | Percentage observation:; ART: 88.7%; SRT: 58.3% | Percentage observation; ART: 79%; SRT: 51%
Michalopoulos, 2014^26^; PRO-ACT study; 15 urologists; 146 patients; Prospective before-after test (own patients) | Post radical prostatectomy with T3 disease or positive SM; Median GC 4.2%; (Range 1.3% to 41.5%) | ART: 27.4%; Observation: 69.9%; Other: 2.7% | ART: 27.4% ^a^; Observation: 71%
Oncotype (No Studies)
Prolaris (No Studies)

Notes.

a As noted above, treatment recommendations were revised for 30.8% of patients.

Abbreviations. ART=adjuvant radiotherapy; BCR=biochemical recurrence; GC=genomic classifier; IQR=interquartile range; PSA=prostate-specific antigen; SRT=salvage radiotherapy.

### Harms

None of the included studies reported on outcomes related to patient harm due to genomic classifier testing. Despite this, acute harms due to the test itself would be expected to be minimal, if any, due to the genomic classifier being run on available tissue specimens. Long-term harms, namely inferior clinical outcomes, due to modified treatment in the absence of the proven predictive ability of the genomic classifier could be present though were not addressed.

### Subgroups

We examined subgroup analyses of a priori prioritized characteristics, specifically race and clinical risk categorization.

#### Race

Two studies reported the impact of genomic classifier tests (both used Oncotype) on treatment recommendations by race.^18,23^ The ENACT trial^23^ recruited 191 participants, the majority of whom were from historically underrepresented racial/ethnic populations, with 70% Black, 12.5% Hispanic or Latino, 1% Asian, and the remaining White. Genomic testing was hypothesized to increase adoption of AS including among Black men, but the study found comparable rates of AS adoption regardless of race (Hispanic, Latino, and Asian patients were pooled due to low sample sizes). Odds ratios for each group suggest that genomic testing increased the odds of undergoing AS, but ratios in all groups were nonsignificant. Lack of significance may be attributable to the small sample size of race/ethnicity subgroups, which likely limited statistical power. The second study^18^ considered the impact of Oncotype testing on selection of AS across groups of White, Black, and “other” Veterans. Black Veterans who underwent Oncotype testing had a higher percentage selecting AS (80%) compared to untested Black Veterans (66%). A similar pattern was noted among White Veterans, with an absolute increase of 11% selecting AS after testing, and 20% absolute increase among Veterans identified as “other” race after testing. There was a significance difference with p-value < 0.01 across all 3 categories.

#### Risk

The impact of genomic classifier test results on treatment recommendations in patients with different risk classifications was explored in the identified studies in 2 ways: among studies that evaluated the effect of receipt of test results by the risk estimate from the test itself and by baseline clinical risk classification (eg, NCCN risk categorization).

### Effect of Tests on Treatment Recommendations at First-line Treatment Decision

Among the studies evaluating the effect of tests on treatment recommendations at the time of first-line treatment choice, 4 Oncotype-based studies^18,20,23,24^ and 1 Prolaris-based study^34^ reported on effect stratified by baseline clinical risk classification. The randomized trial by Murphy et al found no statistically significant association between baseline risk classification of NCCN low or low intermediate and choice of active surveillance as initial treatment.^23^ Across the other observational studies, there was no clear pattern of which baseline clinical risk population more often was described to have a change in treatment plan (Table 8).

Table 8 Test Effect on First-line Treatment Decisions by Baseline Clinical Risk Determination

Study; Total N; Design | Clinical Characteristics | Outcomes
Decipher (No Studies)
Oncotype
Murphy, 2021^23^; ENACT study; 191 patients; Randomized trial | Newly diagnosed; NCCN favorable intermediate or below; Median GPS score: NR | Association intervention arm (test vs no-test) with treatment choice of active surveillance:; - Low: OR = 0.28 (0.05 to 1.50); - Low intermediate: OR for active surveillance = 0.32 (0.10 to 1.08)
Lynch, 2018^18^; 200 (2013–2014); 190 (2015–2016); 6 VA health care systems; Retrospective cohorts before-after institutional testing | Newly diagnosed; NCCN intermediate risk or lower; Median GPS (tested): 26.5 (range 0–61); Risk reclassification:; Lower :12%; Higher: 7% | Treatment recommendation changes most common among NCCN intermediate risk patients:; - 5% decreased intensity; - 22% increased intensity; No statistically significant different in use of active surveillance across NCCN risk groups between tested and untested cohorts (p = 0.20)
Eure, 2017^20^; 247 (before); 258 (after); Comparative cohort before (retrospective) and after (prospective) institutional testing | Newly diagnosed; NCCN intermediate or lower; Median GPS: NR; 23% pts had risk reclassification | Overall change in management plan:; - NCCN very low: 16%; - NCCN low: 28%; - NCCN intermediate: 23%; Choice of active surveillance management:; - NCCN very low:; Untested: 57%; Tested: 88%; - NCCN low:; Untested: 43%; Tested 74%; - NCCN intermediate; Untested: 19%; Tested: 23%; Changes were “directionally consistent with GPS predicted risk”
Badani, 2015^24^; 158 pts; 3 clinical sites; Prospective before-after test (own patients) | Newly diagnosed; NCCN low-intermediate or lower; Median GPS: 21 (IQR range: 13, 32); 38 pts (24%) with risk reclassification post-GPS | Decrease in treatment intensity by NCCN risk:; - Very low: 1/35 (2.8%); - Low: 21/71 (29.6%); - Low intermediate: 3/52 (5.8%); Increase in treatment intensity by NCCN risk:; - Very low: 3/35 (8.6%); - Low: 5/71 (7.0%); - Low intermediate: 6/52 (11.5%)
Prolaris
Crawford, 2014^34^; 305 patients; Prospective pre/post-test result | New diagnosis; AUA risk; Low: 44.3%; Intermediate: 42.9%; High: 12.8%; Median CCP:; −0.71 +/−0.83 | Overall change in treatment recommendations by AUA risk level:; - Low: 31.8%; 24.4% interventional to non-interventional; 7.4% non-interventional to interventional; - Intermediate: 29%; 16.% intervention to non-interventional; 12.2% non-interventional to interventional; - High: 33.3%; 15.4% interventional to non-interventional; 17.9% non-interventional to interventional

Abbreviations. AUA=American Urological Association; CCP=cell cycle progression; GPS=genomic prostate score.

### Test Effect on Treatment Recommendations after Radical Prostatectomy by Test Risk Prediction

#### Decipher

Five studies (6 articles) reported changes to treatment recommendations for patients at the time of radical prostatectomy by test-based risk assessment, all of which were Decipher-based studies (Table 9).^26,27,29,30,36,37^ Overall, patients with genomic classifier or Decipher test results indicating higher risk received lower rates of recommendation for observation post-prostatectomy.

Table 9 Test Effect on Treatment Recommendations After Radical Prostatectomy by Test Risk Prediction

Study; Total N; Design | Clinical Characteristics | Observation Treatment Recommendation; Pre-test | Genomic Classifier Risk Stratification
Decipher
Gore, 2017^36^; PRO-IMPACT study; 19 sites; 265 patients; Prospective before-after test (own patients) | Post radical prostatectomy; non-organ confined prostate cancer or positive surgical margins (ART); or PSA increase or BCR^a^ (SRT); Median GC score:; ART: 6.2% (IQR 0.5 to 44.2); SRT: 6.5% (IQR 0.5 to 62.8) | ART; Observation recommended:; 88%; SRT; Observation recommended:; 60% | Low | Intermediate | High
Gore, 2017^36^; PRO-IMPACT study; 19 sites; 265 patients; Prospective before-after test (own patients) | | ART; Observation recommended:; 88%; SRT; Observation recommended:; 60% | [underlined: ART]; Observation recommended after test results:; 60/63 = 95%; After 12 months:48/140 = 76%; [underlined: SRT]; Observation recommended post test:; 24/34 = 71%; After 12 months:; 16/34 = 47% | [underlined: ART]; Observation recommended after test results:; 24/33 = 73% After 12 months:; 23/33 = 70%; [underlined: SRT]; Observation recommended after test results:; 17/28 = 61%; After 12 months:; 12/28 = 43% | [underlined: ART]; Observation recommended after test results:; 27/44 = 61%; After 12 months:; 27/44 = 61%; [underlined: SRT]; Observation recommended after test results:; 13/44 = 30%; After 12 months:; 12/44 = 27%
Badani, 2015^29^; 110 cases; 51 urologists; Deidentified case history review with and without test | Post radical prostatectomy with undetectable PSA; Median GC 3.85 (min, max: 1.2, 33.4); % reclassified: NR | Observation recommended: 57% | Low | High
Badani, 2015^29^; 110 cases; 51 urologists; Deidentified case history review with and without test | Post radical prostatectomy with undetectable PSA; Median GC 3.85 (min, max: 1.2, 33.4); % reclassified: NR | Observation recommended: 57% | Observation: 80.7% | Observation: 34.6%
Badani, 2013^30^; 12 patient cases (ART); 12 patient cases (SRT); 21 urologists from 18 sites | Post radical prostatectomy with adverse pathology; Median GC: NR | Observation: 47.5% | Observation: 79% | Observation: 8%
Deidentified case history review with and without test
Michalopoulos, 2014^26^; PRO-ACT; 15 urologists; 146 patients; Prospective before-after test (own patients) | Post radical prostatectomy with T3 disease or positive SM; Median GC: 4.2% (Range: 1.3 to 41.5%) | | Low | High ^b^
Michalopoulos, 2014^26^; PRO-ACT; 15 urologists; 146 patients; Prospective before-after test (own patients) | Post radical prostatectomy with T3 disease or positive SM; Median GC: 4.2% (Range: 1.3 to 41.5%) | | - Decrease: 15 (17.1%); - No change: 72 (81.8%); - Increase: 1 (1.1%) | - Decrease: 4 (7.6%); - No change: 28 (52.8%); - Increase: 21 (39.6%)
Shahait, 2021^37^; 398; 2 prospective cohorts | Post radical prostatectomy with adverse pathology | NR | HR = 4.28 (2.81 to 6.50) higher chance of receiving secondary therapy with high GC vs low/intermediate GC
| Median GC: 0.593%
Oncotype (No Studies)
Prolan’s (No Studies)

Notes.

a High/low determination based on Decipher predicted risk relative to average risk for original study population

b Receipt of treatment recommendations higher among patients with high-risk Decipher scores vs low risk (p<0.001).

Abbreviations. ART=adjuvant radiotherapy; BCR=biochemical recurrence; GC=genomic classifier; HR=hazard ratio; IQR=interquartile range; PSA=prostate-specific antigen; SRT=salvage radiotherapy.

## KEY QUESTION 3: AMONG PATIENTS WITH LOCALIZED PROSTATE CANCER, WHAT IS THE PROGNOSTIC EFFECT OF TISSUE-BASED GENOMIC TESTS AFTER ADJUSTING FOR EXISTING PROGNOSTIC CLINICAL FEATURES ON KEY CLINICAL OUTCOMES (eg, BIOCHEMICAL RECURRENCE-FREE SURVIVAL, METASTASES-FREE SURVIVAL) FOLLOWING DEFINITIVE TREATMENT?

### Key Points

- While 39 studies addressed the prognostic ability of genomic classifiers, the clinical classification schemes they were compared to and outcomes assessed varied greatly.
- Only 2 of the 39 studies included prospectively collected cohorts, and only 9 of the 39 studies included patients treated with definitive radiation.
- Patients in these studies were diagnosed from the 1980s to the mid-2010s, a long period that saw many advancements in the diagnosis, treatment, and follow-up of patients with prostate cancer. Despite this, genomic classifiers show a consistent albeit modest improvement in prognosis when compared to clinical models.
- For biochemical recurrence, the Decipher summary hazard ratio (HR) was 1.20 (95% CI [1.00, 1.43]), the Oncotype HRs ranged from 1.10 to 2.73, and the Prolaris summary hazard ratio for BCR was 1.44 (95% CI [1.28, 1.62]).
- For development of metastases, the HR ranged from 1.17 to 2.05 for Decipher, 2.24 to 2.34 for Oncotype, and 2.03 to 4.19 for Prolaris.
- For prostate-cancer-specific mortality, the HRs for Decipher ranged from 1.39 to 1.81, the range for Oncotype was 2.30 to 2.69, and the summary HR for Prolaris was 1.722 (95% CI [1.58, 1.87]).

Thirty-nine studies, including more than 10,000 patients addressed the utility of adding or incorporating genomic classifiers into clinical risk-classification schemes to enhance prognostic accuracy across multiple disease outcomes.^4,6,19,21,22,37–71^ Across studies, there was substantial variability in the clinical risk-classification models, outcome of interest, and statistical measure used to assess the impact of the genomic classifier. Seven studies compared the prognostic ability of the genomic classifier to NCCN risk classification, 22 to CAPRA or CAPRA-S, 1 to AUA, and 24 to a combination of clinical features unique to the study, with a plurality of studies reporting multiple comparisons across clinical risk-classification schemes. Sixteen studies investigated biochemical recurrence, 20 the rate of metastases, and 10 prostate-cancer-specific mortality, all of which were retrospective in design. Five studies included composite endpoints, of which 2 were prospective and the remaining 3 retrospective. Twenty-two studies employed Decipher, 5 Oncotype, and 14 Prolaris, with 1 study investigating all 3 genomic classifiers; however, in the study that included all 3 tests, tissue sample processing and analysis was performed by the institution at which the patients were treated as opposed to the company that developed the test.^40^ Twenty-four studies ran the genomic classifier on prostatectomy tissue,^4,22,37,39–4^,^6,51,52,54,57,59–61,63,64,66,68,71^ 20 on biopsy tissue,^6,19,21,22,38,42,43,46–50,53,55,58,62,65,67,69,71^ and 5 on a combination of the two.^22,42,43,46,71^ At least 26 studies included patients diagnosed prior to 2000,^4,6,19,22,39–41,43,44,46,52–57,59,61–65,67–69,71^ and at least 9 included patients diagnosed prior to 1990.^4,6,22,39,44,54,55,64,69^ One study did not report the timeframe from which the patients were drawn, while another described patients as diagnosed prior to 2017.^42,50^ The majority of studies, 34, included patients who underwent prostatectomy as their initial treatment. Nine studies included patients who were treated with definitive radiation with only 3 studies including patients that solely received definitive radiation.^19,38,43,46,48,49,55,58,67^ Two studies did not report the treatments received.^62,69^

Common risks of bias among included studies for this KQ include exclusion of potentially eligible participants due to insufficient tissue sample or tissue quality to run the genomic classifier test, exclusion of patients lost to follow-up or who might have had adverse outcomes in other health systems, inadequate adjusting for confounders in analysis, limited duration of follow-up, and lack of details about missing data. Less common was having the genomic classifier test run by a lab other than the commercial lab for the specific test type. Eighteen studies were found to have low ROB,^4,6,38,39,41,43,44,4^,^6,48,50,53,60,62–66,68^ 11 moderate ROB,^22,37,47,52,54,57–59,61,67,69^ and 10 high ROB^19,21,40,42,45,49,51,56,71^ (Figure 6). Of note, 17 studies appear to have been sponsored or co-authored by the commercial companies with rights to the genomic classifier tests under study.

Figure 6 Risk of Bias Assessment for Prognostic Studies

Next, we discuss KQ3 results by outcome and genomic classifier studied.

### Biochemical Recurrence

#### Decipher

Four studies evaluated the additional benefit of the Decipher score in predicting biochemical recurrence (BCR).^42,49,58,60^ All 4 were retrospective, 1 had low ROB,^60^ 1 moderate ROB,^58^ and 2 high ROB.^42,49^ For Decipher, the summary estimate HR for BCR across 3 studies (N = 445) was 1.20 (95% CI [1.00, 1.43]; 95% prediction interval [PI] [1.00, 1.43) (Figure 7), indicating a 20% increase in the risk of BCR with a higher Decipher score when clinical classification schemes are also considered. Two studies evaluated patients undergoing radiation and 2 evaluated patients post-prostatectomy.

A low ROB study evaluated 224 men with high-risk pathologic features after prostatectomy.^60^ In a model that included age and CAPRA-S scores, 0.1 unit increases in the Decipher score correlated with a significantly increased risk of BCR with a HR of 1.17 (95% CI [1.04, 1.33]) (Table 10).^60^ However, in the same model, 1 unit increases in the CAPRA-S scores predicted a similar increase in risk of BCR with a HR of 1.14 (95% CI [1.01, 1.29]).^60^ The AUC remained in the range generally considered to be poor with a non-significant increase in the AUC from 0.64 (0.56 to 0.63) to 0.69 (0.61 to 0.76) after the addition of the Decipher score to the CAPRA-S score for discrimination of BCR at 10 years (Figure 8).^60^

In a moderate ROB study of 100 men with either intermediate- or high-risk prostate cancer, there was no evidence of an improvement in prognostic ability per 0.1 increase in Decipher score in either a model with NCCN (HR = 1.16, 95% CI [0.96, 1.141]) or CAPRA (HR = 1.08, 95% CI [0.89, 1.32]) classification schemes.^58^

In a high ROB retrospective study of 121 men with intermediate-risk prostate cancer who underwent dose-escalated radiation therapy alone without ADT,^49^ Decipher score as a continuous variable was significantly associated with an increased risk of BCR (HR = 1.36, 95% CI [1.09, 1.71]) while unfavorable versus favorable intermediate risk classification was not. Additionally, even though Decipher’s AUC for BCR at 5 years (0.78; 95% CI [0.59, 0.91]) was not significantly different from the NCCN classification (0.56; 95% CI [0.43, 0.66]), a combined NCCN and Decipher model improved the AUC for BCR to 0.85 (95% CI [0.73, 1.00]). Concerns for potential ROB came from a lack of clarity of participation by a potentially eligible pool of patients and a lack of information about missing data.

The other high ROB study evaluated the prognostic ability of the Decipher score in 81 patients who underwent prostatectomy and post-operative radiation.^42^ In a model with multiple pathologic features and the Decipher score as a categorical value, only receipt of salvage versus adjuvant therapy and the Decipher score were significantly associated with risk of BCR. Compared to a high Decipher score, low (HR = 0.32; 95% CI [0.13, 0.75]) and intermediate (HR = 0.4; 95% CI [0.18, 0.89]) Decipher scores were associated with a lower risk of BCR. This study also reported an acceptable AUC of 0.742 (95% CI [0.643, 0.84]) for a model with pathologic features and the Decipher score; however, it is unclear how much Decipher added value here as neither an AUC for pathologic features nor Decipher score alone was provided. ROB assessment for this study was primarily driven by a lack of information around the source populations for the cohorts, the recruitment time period, or how many samples were excluded due to insufficient or inadequate tissue.

#### Oncotype

Three retrospective studies, including 2 low ROB studies and 1 moderate ROB study, evaluated the prognostic ability of the Oncotype score for BCR. All studies used biopsy tissue from patients who underwent prostatectomy.^47,53,65^ The study-specific HRs ranged from 1.10 (95% CI [1.10, 1.21]) to 2.7 (95% CI [1.84, 3.96]). These 3 studies were not combined in a meta-analysis due to underlying conceptual heterogeneity.

In a cohort of 402 men, a model accounting for NCCN risk classification showed an increase in BCR risk for every increase in 20 units of the Oncotype score with an HR of 2.73 (95% CI [1.84, 3.96]).^65^ In this model, NCCN risk grouping was not a significant predictor of BCR.

In a retrospective study of 257 men treated from 1995 to 2010, the Oncotype score per 20 units had significant increased risk in BCR with HRs of 2.11, 2.41, and 2.30 in models containing NCCN, AUA, or CAPRA classification schemes, respectively.^53^ NCCN and CAPRA remained significant in their respective models, while AUA did not. There was a corresponding increase in the AUC for BCR from NCCN alone to NCCN with Oncotype (0.59 to 0.68); however, it remained below generally acceptable levels of discrimination and confidence intervals were not presented to assess significance.

Finally, in a retrospective of 215 men who underwent prostatectomy following a course of active surveillance, Oncotype was associated with an increased risk of BCR per 5 unit increase in a model that included the CAPRA score (HR = 1.10; 95% CI [1.00, 1.21]).^47^ This study was found to be at moderate risk of bias due to concerns related to study attrition and specificity of prognostic factor measurement.

#### Prolaris

Nine retrospective studies (3 low ROB, 1 moderate ROB, and 5 high ROB) evaluated the ability of the Prolaris or cell cycle progression score (CCP) to predict BCR. The summary effect estimate across these studies showed an increased risk of BCR with increasing Prolaris score with an HR of 1.44 (95% CI [1.28, 1.62]; 95% PI [1.28, 1.62]). Eight studies were performed in patients who underwent prostatectomy,^4,21,45,50,51,56,68,71^ and 1 study in patients who underwent definitive radiation,^67^ with biopsy and prostatectomy tissue each analyzed in 5 of the 9 studies.

One low ROB study evaluated BCR post-prostatectomy among 246 men and found an HR of 1.7 (95% CI [1.3, 2.3]) for CCP as a continuous variable in a model with CAPRA-S. In this study, CCP as a categorical variable from 0 to 1 (HR = 5.2, 95% CI [1.2, 21.7]) or greater than 1 (HR = 9.5, 95% CI [2.0, 45.2]) were significant; however, CCP as a categorical variable from −1 to 0 was not (HR = 3.4, 95% CI [0.8, 14.1]) in a model incorporating the CAPRA-S score.^68^ The Prolaris score was also predictive of BCR in another low ROB study of 424 men who underwent prostatectomy prior to 2017.^50^ When incorporating CAPRA-S, CCP had an HR of 1.51 (95% CI [1.08, 2.11]) for BCR.^50^ This corresponded with an acceptable AUC for the CCP and CAPRA-S of 0.72 (95% CI was not reported nor was AUC for CCP or CAPRA-S alone). The third low ROB study demonstrated an HR of 1.74 (95% CI [1.39, 2.17]) for the CCP per unit increase in a cohort of 336 men who underwent prostatectomy when included in a model with other pathologic characteristics.^4^

The other 5 studies reporting the relationship between CCP and BCR among men post-prostatectomy were found to be at high ROB primarily due to lack of clarity about participation among potentially eligible patients, study attrition, and non-standard or unclear prognostic factor measurement. The first included 100 men post-prostatectomy and found an HR of 1.373 (95% CI [1.006, 1.874]) in a model containing CCP per unit increase and CAPRA score. They also demonstrated HRs for high versus low CCP of 10.912 (95% CI [3.0, 39.7]) and 7.481 (2.1, 26.4) for intermediate versus low CCP with notably wide confidence intervals.^45^ This corresponded to a C-index for prediction of BCR of 0.77 (95% CI [0.69, 0.85]) which was not significantly greater than of the CAPRA-S score (0.71; 95% CI [0.63, 0.79]) or CCP (0.74; 95% CI [0.66, 0.83]) alone.^45^ In a second retrospective cohort of 474 men from the 2000s, HRs of 1.24 (95% CI [1.01, 1.52]) and 1.28 (95% CI [1.03, 1.59]) were found in models including CAPRA-S or multiple pathologic characteristics, respectively, with the latter including Ki-67 and PTEN expression.^51^ In the third study of 236 patients (76 Veterans) with low-risk prostate cancer who underwent prostatectomy, the HR for BCR with CCP as a continuous variable was 1.41 (95% CI [1.02, 1.96]) in MVA incorporating CAPRA score.56 In this study, similar albeit poor AUCs for BCR were observed at 5 (0.662) and 10 (0.65) years post-prostatectomy for models with CCP and CAPRA compared to CAPRA alone at 5 (0.557) and 10 (0.542) years. A fourth retrospective study including only 52 patients postprostatectomy reported a non-statistically significant HR for CCP in a model with CAPRA (1.68; 95% CI [0.54, 5.23]); however, the AUC for the CCP and CAPRA combined was 0.86 (95% CI or AUC for CCP or CAPRA alone not reported).^21^ Finally, the fifth cohort including 582 patients postprostatectomy (176 Veterans) demonstrated an HR of 1.47 (95% CI [1.23, 1.76]) when incorporating pathologic features in MVA model for BCR.^71^

The 1 study assessing BCR following definitive radiation included 141 Veterans treated between 1991 and 2006. In a model with pathologic features and concurrent ADT use, there was an increased risk of BCR with increasing Prolaris score with a HR of 2.11 (95% CI [1.05, 4.25]).^67^ In this moderate ROB study, a small increase in the AUC was observed from 0.78 with clinical features alone to 0.80 with clinical features and CCP score, bringing the AUC into what is generally considered excellent discrimination.

Figure 7 Hazard Ratio Forest Plot for Biochemical Recurrence by Test Type (Decipher, Oncotype, Prolaris)^a^ a Notes. Model includes CAPRA, PSA, age, tissue source (confirmatory vs diagnostic biopsy), clinical institution (UCSF vs other), genomic prostate score testing (clinical care vs research).

Figure 8 C-statistic Forest Plot for Biochemical Recurrence by Test Type (Decipher, Prolaris)^a^ a Notes. Model includes tumor stage (pT3–4 vs pT2), PSA pre-PORT, surgical margins (positive vs negative), ISUP Grade Group (2,3,4–5 vs 1), PORT modality (salvage vs adjuvant), intraductal carcinoma and cribriform architecture (positive vs negative).

Table 10 Studies Reporting Biochemical Recurrence

Study; Total N; Design; Risk of Bias (ROB) | Clinical Characteristics; Tissue Source; Treatment; Study Duration | Model Variables | Results (95% CI)
Decipher
Berlin, 2019^49^; 121; Retro; High ROB | NCCN intermediate risk; Biopsy; Dose-escalated, image-guided RT without ADT; 2005–2011 | NCCN classification; unfavorable vs favorable intermediate risk | HR = 1.36 (1.09 to 1.71)
Berlin, 2019^49^; 121; Retro; High ROB | NCCN intermediate risk; Biopsy; Dose-escalated, image-guided RT without ADT; 2005–2011 | NCCN | AUC (5 years); Clinical features 0.56 (0.43 to 0.66); Clinical features and test 0.85 (0.73 to 1.00)
Ramotar, 2022^42^; 81; Retro; High ROB | Post “maximal local therapies” (RP and PORT) with pathology slides available for review; Biopsy, RP; RP and RT; NR | Tumor stage; pT3–4 vs pT2; PSA pre-PORT; Surgical margins; positive vs negative; ISUP Grade Group; 2,3,4–5 vs 1; PORT modality; salvage vs adjuvant; IDC/CA; positive vs negative | Intermediate Decipher vs high; HR = 0.4 (0.1 to, 0.89); Low Decipher vs high HR = 0.32 (0.13 to 0.75)
Ramotar, 2022^42^; 81; Retro; High ROB | Post “maximal local therapies” (RP and PORT) with pathology slides available for review; Biopsy, RP; RP and RT; NR | Tumor stage; pT3–4 vs pT2; PSA pre-PORT; Surgical margins; positive vs negative; ISUP Grade Group; 2,3,4–5 vs 1; PORT modality; salvage vs adjuvant; IDC/CA; positive vs negative | AUC; Clinical features and test 0.742 (0.643 to 0.84)
Nguyen, 2017b^58^; 100; Retro; Moderate ROB | NCCN intermediate and high risk treated with RT and ADT; Biopsy; RT and ADT | NCCN; High vs intermediate risk | HR = 1.16 (0.96 to 1.41)
Glass, 2016^60^; 224; Retro; Low ROB | RP with high-risk pre-op features (PSA > 20 or Gleason score ≥ 8) pT3, or +SM; RP; RP; 2001–2013 | CAPRA-S; Age at diagnosis | HR = 1.17 (1.04 to 1.33)
Glass, 2016^60^; 224; Retro; Low ROB | RP with high-risk pre-op features (PSA > 20 or Gleason score ≥ 8) pT3, or +SM; RP; RP; 2001–2013 | CAPRA-S | AUC; Clinical features 0.64 (0.56 to 0.73); Clinical features and test 0.69 (0.61 to 0.76)
Oncotype
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2010 | NCCN; High vs low and very low; Intermediate vs low and very low | HR = 2.11 (1.41 to 3.14)
Kornberg, 2019^47^; 215; Retro; Moderate ROB | Active surveillance patients who had RP ≥ 6 months after starting. Patients had organ confined Gleason 3 + 3 or low volume 3 + 4 prostate cancer with PSA < 20 and CAPRA score < 6; Biopsy; RP; 2001–2016 | CAPRA, Age at diagnosis; PSA density at time of genomic test; Tissue source; Confirmatory vs diagnostic biopsy; Clinical institution; UCSF vs other; GPS testing; Clinical care vs research | HR = 1.10 (1.00 to 1.21)
Cullen, 2015^65^; 402; Retro; Low ROB | Biopsy Gleason score 6 or 7, PSA ≤ 20, ≤ cT2, and RP ≤ 6 months after diagnosis; Biopsy; RP; 1990–2011 | NCCN; Low vs very low; Intermediate vs very low | HR = 2.73 (1.84 to 3.96)
Cullen, 2015^65^; 402; Retro; Low ROB | Biopsy Gleason score 6 or 7, PSA ≤ 20, ≤ cT2, and RP ≤ 6 months after diagnosis; Biopsy; RP; 1990–2011 | NCCN | AUC; Clinical features only 0.59 (NR); Clinical features and test 0.68 (NR)
Prolaris
Cuzick, 2011^4^; 336; Retro; Low ROB | RP without neoadjuvant therapy; RP; RP; 1985–1995 | Log(1+baseline PSA); Gleason score; 7, >7 vs <7; Pathological stage; Surgical margins | HR = 1.74 (1.39 to 2.17)
Shangguan, 2019^45^; 100; Retro; High ROB | Adverse pathology (SVI, ECE, positive surgical margins) after RP; RP; RP; 2010–2014 | CAPRA score; Age | HR = 1.373 (1.006 to 1.874)
Shangguan, 2019^45^; 100; Retro; High ROB | Adverse pathology (SVI, ECE, positive surgical margins) after RP; RP; RP; 2010–2014 | CAPRA score; Age | High Prolaris vs low; HR = 10.912 (3.0 to 39.691)
Shangguan, 2019^45^; 100; Retro; High ROB | Adverse pathology (SVI, ECE, positive surgical margins) after RP; RP; RP; 2010–2014 | CAPRA score; Age | Intermediate Prolaris vs low; HR = 7.481 (2.118 to 26.425)
Shangguan, 2019^45^; 100; Retro; High ROB | Adverse pathology (SVI, ECE, positive surgical margins) after RP; RP; RP; 2010–2014 | CAPRA score | AUC; Clinical features; 0.705 (0.625 to 0.785); Clinical features and test; 0.771 (0.689 to 0.853)
Leapman, 2018^50^; 424; Retro; Low ROB | Clinically localized, treated with RP; Biopsy; RP; Prior to 2017 | CAPRA-S | HR = 1.51 (1.08 to 2.11)
Leapman, 2018^50^; 424; Retro; Low ROB | Clinically localized, treated with RP; Biopsy; RP; Prior to 2017 | CAPRA-S | AUC; Clinical features and test; 0.72 (NR)
Leon, 2018^51^; 474; Retro; High ROB | Treated with RP; RP; RP; 2000–2007 | CAPRA-S score; (other regression components not clear) | HR = 1.24 (1.01 to 1.52)
Tosoian, 2017^56^; 236; Retro; High ROB | RP for Gleason score ≤6; Biopsy; RP; 1994–2006 | CAPRA | HR = 1.41 (1.02 to 1.96)
Tosoian, 2017^56^; 236; Retro; High ROB | RP for Gleason score ≤6; Biopsy; RP; 1994–2006 | CAPRA | AUC (5 years); Clinical features; 0.557 (NR); Clinical features and test; 0.662 (NR)
Tosoian, 2017^56^; 236; Retro; High ROB | RP for Gleason score ≤6; Biopsy; RP; 1994–2006 | CAPRA | AUC (10 years); clinical features; 0.542 (NR); Clinical features and test; 0.65 (NR)
Oderda, 2017^21^; 52; Retro; High ROB | T reated with RP; Biopsy; RP; 2013–2015 | CAPRA | HR = 1.68 (0.54 to 5.23)
Oderda, 2017^21^; 52; Retro; High ROB | T reated with RP; Biopsy; RP; 2013–2015 | | AUC; Clinical test and features; 0.86 (NR)
Freedland, 2013^67^; 141; Retro; Moderate ROB | Treated with RT; Biopsy; RT; 1991–2006 | Log(1 + PSA); Gleason score; 7, >7 vs <7; Percent positive cores; Concurrent ADT | HR = 2.11 (1.05 to 4.25)
Freedland, 2013^67^; 141; Retro; Moderate ROB | Treated with RT; Biopsy; RT; 1991–2006 | Log(1 + PSA); Gleason score; Percent positive cores; Concurrent ADT | AUC; Clinical features; 0.78 (NR); Clinical features and test; 0.80 (NR)
Bishoff, 2014^71^; 582; Retro; High ROB | Clinically localized, treated with RP; Biopsy, RP; RP; 1994–2006 | Log(1 + PSA); Gleason score; 7, >7 vs <7; Percent positive cores; Adjuvant treatment; Age at diagnosis | HR = 1.47 (1.23 to 1.76)
Cooperberg, 2013^68^; 413; Retro; Low ROB | Treated with RP without adjuvant or neoadjuvant therapy and with >5 years follow-up; RP; RP; 1994–2011 | CAPRA-S | HR = 1.7 (1.3 to 2.3)
Cooperberg, 2013^68^; 413; Retro; Low ROB | Treated with RP without adjuvant or neoadjuvant therapy and with >5 years follow-up; RP; RP; 1994–2011 | CAPRA-S | CCP Score; > −1 to 0 vs ≤ −1; HR = 3.4 (0.8 to 14.1)
Cooperberg, 2013^68^; 413; Retro; Low ROB | Treated with RP without adjuvant or neoadjuvant therapy and with >5 years follow-up; RP; RP; 1994–2011 | CAPRA-S | CCP Score; > 0 to 1 vs ≤ −1; HR = 5.2 (1.2 to 21.7)
Cooperberg, 2013^68^; 413; Retro; Low ROB | Treated with RP without adjuvant or neoadjuvant therapy and with >5 years follow-up; RP; RP; 1994–2011 | CAPRA-S | CCP Score; > 1 vs ≤ −1; HR = 9.5 (2.0 to 45.2)

Abbreviations. ECE=extra-capsular extension; PSA=prostate specific antigen; SVI=seminal vesicle involvement.

### Metastases

#### Decipher

Sixteen studies with 3,587 participants addressed the ability of the Decipher score to predict metastases following definitive treatment of prostate cancer, including 15 retrospective studies and 1 secondary analysis of a prospective, randomized trial.^6,19,22,40,41,43,44,49,52,55,58,59,61,63,64^ Across 9 studies (N = 2,139), the summary effect estimate showed an increase in risk of metastases with continuous increase in Decipher score with an HR of 1.32 (95% CI [1.22, 1.44]; 95% PI [1.15, 1.52]) (Figure 9). Notably, these 16 studies drew on patients diagnosed from 1987 and 2016, over which time management of prostate cancer evolved. Six studies were found to have low ROB, 5 moderate ROB, and 5 high ROB. The number of metastatic events in these studies were low, ranging from 5 to 104, leading to large variability in reported findings.

The first low ROB study was an ancillary analysis of data from 352 men treated on RTOG 9601, a phase III prospective randomized trial evaluating the addition of 2 years of ADT to post-prostatectomy radiation. Patients eligible for this study had a rising PSA to 0.2 to 4.0 following prostatectomy with pathology showing either T2N0 disease with positive margins or T3N0 disease.^41^ This study demonstrated an HR of 1.17 (95% CI [1.05 to 1.32]) for metastases for Decipher as a continuous variable in a model including clinical and pathological characteristics as well as treatment received (ADT or placebo) as part of the phase III study. When considered as a categorical variable, Decipher high versus low scores had an HR of 1.74 (95% CI [1.08, 2.84]) accounting for the same variables used in the model above (Table 11). Of note, this report was underpowered to detect a statistically significant interaction between the Decipher score and the effect of ADT and therefore did not demonstrate the Decipher score as a predictive biomarker for ADT use.

A second low ROB study included 405 Veterans with prostate cancer and employed multiple clinical classification schemes while evaluating Decipher as both a continuous variable (per 0.1 units) and as a categorical variable.^43^ In models with Decipher as a continuous variable, the HRs for metastases were 1.34 (95% CI [1.19, 1.50]) and 1.33 (95% CI [1.19, 1.48]) with incorporation of NCCN and CAPRA classification schemes, respectively. As a categorical variable, HRs for metastases were 2.95 (95% CI [1.75, 4.98]) and 3.09 (95% CI [1.88, 5.06]) comparing high (>0.6) and low (<0.45) Decipher scores in models with NCCN and CAPRA classifications, respectively (Figure 10). In addition, the AUC for metastases at 5 years increased with the addition of the Decipher score to almost acceptable discrimination; specifically, the AUC increased from 0.46 (95% CI [0.38, 0.53]) to 0.67 (95% CI [0.60, 0.75]) and from 0.59 (95% CI [0.50, 0.67]) to 0.71 (95% CI [0.65, 0.78]) when including the Decipher score with NCCN and CAPRA models, respectively (Figure 11).

In another low ROB study of 548 Veterans who had undergone prostatectomy, Decipher as a categorical variable showed an HR of 9.60 (95% CI [3.51, 32]) for prediction of metastases when comparing high to low scores and 6.51 (95% CI [2.33, 21.8]) for intermediate to low scores.^44^ The number of events in this cohort was 37, leading to the large confidence intervals. In the fourth low ROB study, a nested case control design was used to create 2 cohorts of men post-prostatectomy: one including patients with either no evidence of recurrence or biochemical recurrence only and one with patients with clinical metastases.^6^ The authors then demonstrated an increased odds of metastases with every 10% increase in Decipher score in a model incorporating multiple pathologic and clinical factors (OR = 1.36, 95% CI [1.16, 1.60]). In addition, they reported an AUC of 0.74 for a model with Decipher and clinical features as compared to an AUC of 0.69 for clinical features alone, although CI were not reported. In another low ROB study of 188 patients limited to those who received post-prostatectomy radiation, models with CAPRA-S showed similar HR for metastases with Decipher of 1.69 (95% CI [1.24, 2.31]) and a significant increase in the AUC from 0.66 (95% CI [0.56, 0.78]) to 0.85 (95% CI [0.79, 0.93]).^63^ Finally, Klein et al reported ORs for the Decipher score of 1.43 and 1.48 for metastases with the continuous Decipher score in models with CAPRA-S or clinical features, respectively.^64^ Including Decipher with clinical features in this study led to a non-significant increase in the AUC to 0.78 (95% CI [0.68, 0.89]) compared to 0.72 (95% CI [0.6, 0.84]) with clinical features alone.

Four of the 5 moderate ROB studies evaluated the additive predictive value of Decipher for metastases reported similar findings. One retrospective study of 260 men observed an HR of 1.32 (95 CI [1.17, 1.51]) for metastases with Decipher by 0.1 unit increase in a model with CAPRA-S.^61^ In addition, the AUC for metastases at 10 years increased from 0.77 (95% CI [0.69, 0.85]) for CAPRA-S alone to 0.87 (95% CI [0.77, 0.94]) for CAPRA-S and Decipher score, although this was not significant. A second retrospective study including 422 patients with adverse pathology on radical prostatectomy^59^ included CAPRA-S and radiation treatment type in their model and reported a HR of 1.28 (1.08, 1.52) for metastases with Decipher. A third study of 100 intermediate and high-risk patients who underwent radiation combined with ADT found that the Decipher score had an HR of 1.37 (95% CI [1.06, 1.78]) in a model with NCCN.^58^ In a fourth small study of 57 men with high-risk clinical or pathologic features, the Decipher score had an HR of 1.64 (95% CI [1.11, 2.42]) for metastasis development in a model including the CAPRA-S score.^22^ In this same study, the addition of the Decipher score to NCCN classification led to an excellent AUC for metastases at 0.88 (95% CI [0.76, 0.96]) versus 0.75 (95% CI [0.64, 0.87]) for NCCN classification alone. The fifth moderate ROB study included 150 men with a persistent PSA following prostatectomy and demonstrated similar HRs with wide confidence intervals for metastases when Decipher as a categorical variable of high versus low and intermediate when included in a model with CAPRA-S (HR 8.72; 95% CI [2.25, 39.8]) or clinical features (HR 5.61; 95% CI [1.48, 22.7]).^52^ The latter corresponded with a non-significant increase in AUC from 0.69 (95% CI [0.41, 0.89]) with clinical features alone to 0.83 (95% CI 0.70, 1.00) with clinical features and the Decipher score.

The remaining 5 studies were retrospective, high ROB studies due to variable levels of concern related to inability to determine proportion of participating eligible patients, non-standard prognostic factor measurement, and study attrition. One study included 121 intermediate-risk patients who underwent radiation alone as definitive treatment and demonstrated an HR of 2.05 (95% CI [1.24, 4.24]) for metastases in a MVA model including NCCN classification.^49^ When NCCN classification was replaced in the model by clinical features, a similar HR was obtained (2.07 95% CI [1.17, 5.24]). AUC improved numerically in this study by adding the Decipher score to clinical features alone (0.89 vs 0.86, respectively).

The remaining 4 high ROB studies all included patients who underwent prostatectomy, with 3 that also included patients treated with definitive radiation. In the 1 study with both prostatectomy and radiation patients, a model containing both clinical features and treatment received demonstrated an increased risk of metastases associated with Decipher with an HR of 1.39 (95% CI [1.09, 1.8]).^55^ Additionally, this study of 235 patients showed that the incorporation of Decipher score into a model with NCCN improved the AUC for prediction of metastases from 0.66 (95% CI [0.53, 0.77]) to 0.74 (95% CI [0.66, 0.82]), although this increase was not significant. A validation study of 235 patients revealed an AUC of 0.84 (95% CI [0.61, 0.93]) for a combination of clinical and genomic characteristics, compared to 0.68 (95% CI [0.64, 0.73)] for NCCN classification alone.^19^ In addition, their clinical-genomic classification scheme of low, intermediate, and high risk showed HRs with wide confidence intervals of 22.3 (95% CI [2.9, 2,863.8]) and 61.6 (95% CI [8.1, 7,914.9]) for intermediate and high risk as compared to low risk when stratified by treating institution and adjusted for treatment received. In a study limited to 160 patients with Gleason Grade Group 2–4 prostate cancer, the predictive ability for metastases for all 3 genomic classifier tests was assessed; specifically, with the addition of Decipher, the AUC increased from 0.55 (95% CI [0.5, 0.6]) to 0.74 (95% CI [0.69, 0.78]).^40^

#### Oncotype

Three retrospective studies (2 low ROB and 1 high ROB) evaluated the prognostic ability of the Oncotype score to predict metastases in men who underwent prostatectomy.^39,40,53^ The 2 low ROB studies reported similar findings supporting an modest additive value of Oncotype test per 20 units when combined with standard clinical features or risk schemas. The first, a low ROB study, showed an HR of 2.34 (95% CI [1.42, 3.86]) for Oncotype by 20 units in a model with NCCN classification among 259 patients who received radical prostatectomy within 12 months of diagnosis.^53^ Similar results for the Oncotype score were seen with models including AUA classification (HR 2.51 95% CI [1.49, 4.23]) and CAPRA score (HR 2.63 95% CI [1.58, 4.36]). This corresponded to an increase in AUC from 0.66 with NCCN classification alone to 0.75 with NCCN and Oncotype features, although 95% CI were not provided to assess significance. The second low ROB cohort included 428 patients treated with prostatectomy between 1987 and 2004 and found that increases in Oncotype score per 20 units were associated with an increased risk of metastases in a model with clinical features (HR = 2.24; 95% CI [1.49, 3.53]), and AUC increased from 0.772 to 0.824 when incorporating Oncotype with clinical features compared to clinical features alone.^39^ Finally, in the same high ROB study that assessed the additive prognostic value of all 3 tests in 1 cohort of patients, the Oncotype score had an AUC of 0.65 (95% CI [0.6, 0.7]) compared to 0.55 (95% CI [0.5, 0.6]) for clinical features alone.^40^

#### Prolaris

Four retrospective studies addressed the additive prognostic value of the Prolaris test for metastases.^40,46,48,71^ The 2 low ROB studies with the same first author (Canter) reported similarly sized increases in metastatic risk associated with increases in Prolaris score. The first (2020) included 1062 patients from 4 institutions (131 Veterans) who had undergone prostatectomy or radiation therapy with or without ADT. In a model that included the CAPRA score and treatment received, CCP had an HR of 2.21 (95% CI [1.64, 2.98]) for metastases.^46^ This increased risk translated to an improvement in AUC from 0.86 to 0.89 when the CCP score was combined with the CAPRA score. The second study by the same author (2019) included a cohort of 767 men, some of whom were included in the previously noted Canter paper, who underwent either definitive radiation or prostatectomy.^48^ In a model containing the CAPRA score, treatment received, and race, the HR for the per unit increase in CCP was 2.03 (95% CI [1.47, 2.78]). The AUC for CAPRA only increased from 0.88 to 0.9 with the addition of CCP.

The other 2 studies evaluating the additive predictive value of Prolaris for metastases had high ROB but reported findings in the same direction and similar magnitude. First, 1 study (N = 582) that included patients post-prostatectomy was found to have multiple potential sources of risk of bias including study participation and measurement of both prognostic factors and outcomes. In a model that included clinical features, the HR for the CCP score was found to be 4.19 (95% CI [2.08, 8.45]).^71^ Finally, the other high ROB study was the same study which evaluated AUC for all 3 relevant genomic classifier tests and showed an AUC of 0.73 (95% CI [0.69, 0.78]) for the CCP score compared to 0.55 (95% CI [0.5, 0.6]) for clinical features alone.^40^

Figure 9 Hazard Ratio Forest Plot for Metastasis by Test Type (Decipher, Oncotype, Prolaris)

Notes. ^a^ Model includes age (≥65 vs <65), race (Black vs non-Black) Gleason score (8–10 vs ≤7), T stage (pT3 vs pT2), PSA, positive surgical margins, PSA nadir status (non-nadir vs nadir <0.5), ADT vs placebo; ^b^ Model includes age, log2 (PSA), grade group, clinical stage, first-line treatment RP, first-line treatment RT ADT; ^c^ Model includes CAPRA-S, treatment (adjuvant radiation vs minimal residual disease salvage radiation, salvage radiation, no radiation); ^d^ CAPRA, treatment institutional cohort; ^e^ CAPRA, ancestry (Black vs non-Black), primary treatment.

Figure 10 Hazard Ratio for Categorical Studies Reporting Metastasis by Test Type (Decipher)

Notes. ^a^ Treatment, age, Black vs non-Black, Gleason, T score, PSA, margin status, nadir, Decipher (high vs low); ^b^ CAPRA-S, age, Black vs non-Black, Decipher (intermediate vs low); ^c^ CAPRA-S, age, Black men vs non Black men, Decipher (high vs low risk); ^d^ CAPRA-S, PSA, Decipher (high vs low/intermediate); ^e^ Age, PSA, Grade Group, T-stage, Decipher (high vs low); ^f^ Clinical-genomic risk grouping NCCN + Decipher (intermediate vs low); ^g^ Clinical-genomic risk grouping NCCN + Decipher (high vs low).

Figure 11 C-statistic Forest Plot for Metastasis and Decipher

Table 11 Studies Reporting Metastases

Study; Total N; Design; Risk of Bias (ROB) | Clinical Characteristics; Tissue Source; Treatment; Study Duration | Model Variables | Results (95% CI)
Decipher
Erho, 2013^6^; 186; RCC; Low ROB | Treated with RP with no evidence of recurrence, BCR only, or metastasis within 5 years of RP; RP; RP; 1987–2001 | Pre-op PSA; Pathologic Gleason score ≥8; SVI; Tumor volume; Lymph node involvement; Positive surgical margins; ECE | OR = 1.36 (1.16, 1.60)
Erho, 2013^6^; 186; RCC; Low ROB | Treated with RP with no evidence of recurrence, BCR only, or metastasis within 5 years of RP; RP; RP; 1987–2001 | Pre-op PSA; Pathologic Gleason score ≥8; SVI; Tumor volume; Lymph node involvement; Positive surgical margins; ECE | AUC; Clinical features 0.69 (NR); Clinical features and test; 0.74 (NR)
Feng, 2021^41^; 351; Retrospective ancillary study of a phase III trial; Low ROB | Treated with RP and PLND with pT2N0M0 and positive surgical margins or pT3N0M0, and PSA of 0.2–4 at least 8 weeks after surgery; KPS ≥ 80; No prior therapy other than short period ADT; No liver disease; Life expectancy of ≥10 years; RP; RP and RT ±2 years ADT; 1998–2003 | Age: ≥65 vs <65; Race: Black vs non-Black; Gleason score: 8–10 vs ≤7; T stage: pT3 vs pT2; PSA at trial entry; Positive surgical margins; PSA nadir status; Non-nadir vs nadir (<0.5); ADT vs placebo | HR = 1.17 (1.05, 1.32)
Feng, 2021^41^; 351; Retrospective ancillary study of a phase III trial; Low ROB | | Age: ≥ 65 vs <65; Race: Black vs non-Black; Gleason score: 8–10 vs ≤ 7; T stage:; pT3 vs pT2; PSA at trial entry; Positive surgical margins; PSA nadir status; Non-nadir vs nadir (<0.5); ADT vs placebo | Decipher; High/intermediate vs low; HR = 1.74 CI (1.08, 2.84)
Tosoian, 2020^43^; 405; Retro; Low ROB | cT3a-T4, or PSA >20, or Gleason Grade Group 4–5 with no neoadjuvant ADT or evidence of nodal disease prior to RP; Biopsy, RP; RP or RT+ADT; 1995–2005 | Age; PSA; Grade Group; 4,5 vs 1–3; T stage; T2, T3/4 vs T1 | Decipher; High vs low; HR = 2.95 (1.79, 4.87); Intermediate vs low; 1.43 (0.80, 2.53)
Tosoian, 2020^43^; 405; Retro; Low ROB | cT3a-T4, or PSA >20, or Gleason Grade Group 4–5 with no neoadjuvant ADT or evidence of nodal disease prior to RP; Biopsy, RP; RP or RT+ADT; 1995–2005 | NCCN; Very high vs high risk | 1.34 (1.19, 1.50)
Tosoian, 2020^43^; 405; Retro; Low ROB | cT3a-T4, or PSA >20, or Gleason Grade Group 4–5 with no neoadjuvant ADT or evidence of nodal disease prior to RP; Biopsy, RP; RP or RT+ADT; 1995–2005 | NCCN; Very high vs high risk | Decipher; High vs low; HR = 2.95 (1.75, 4.98); Intermediate vs Low; 1.56 (0.87, 2.80)
Tosoian, 2020^43^; 405; Retro; Low ROB | cT3a-T4, or PSA >20, or Gleason Grade Group 4–5 with no neoadjuvant ADT or evidence of nodal disease prior to RP; Biopsy, RP; RP or RT+ADT; 1995–2005 | NCCN | AUC; Clinical features; 0.46 (0.38, 0.53); Clinical features and test; 0.67 (0.60, 0.75)
Berlin, 2019^49^; 121; Retro; High ROB | NCCN intermediate risk, treated with curative intent DE-IGRT without ADT; Biopsy; 2005–2011 | NCCN unfavorable vs favorable intermediate risk | HR = 2.05 (1.24, 4.24)
Berlin, 2019^49^; 121; Retro; High ROB | NCCN intermediate risk, treated with curative intent DE-IGRT without ADT; Biopsy; 2005–2011 | Age; Pre-diagnostic PSA; T stage; cT2b/c vs cT1/2a; ISUP grade; 3 vs 1 and 2; Percent positive cores; ≥ 50 vs <50 | HR = 2.07 (1.17, 5.24)
Berlin, 2019^49^; 121; Retro; High ROB | NCCN intermediate risk, treated with curative intent DE-IGRT without ADT; Biopsy; 2005–2011 | NCCN | AUC; Clinical features; 0.54 (0.32, 0.67); Clinical features and test; 0.89 (0.68, 1.00)
Nguyen, 2017a^55^; 235; Retro; High ROB | NCCN intermediate or high risk treated with RT with or without ADT or prostate cancer with adverse pathology on RP; Biopsy; RP or RT with or without ADT; 1987–2014 | Patient’s age; Log2 (PSA) Grade; Group Clinical stage; First-line treatment; RP First-line treatment RT ADT | HR = 1.39 (1.09, 1.8)
Nguyen, 2017a^55^; 235; Retro; High ROB | NCCN intermediate or high risk treated with RT with or without ADT or prostate cancer with adverse pathology on RP; Biopsy; RP or RT with or without ADT; 1987–2014 | NCCN | AUC; Clinical features; 0.66 (0.53, 0.77); Clinical features and test; 0.74 (0.66, 0.82)
Nguyen, 2017b^58^; 100; Retro; Moderate ROB | NCCN intermediate and high risk, treated with RT and ADT; Biopsy; RT+ADT; 2001–2013 | NCCN high | HR = 1.37 (1.06, 1.78)
Klein, 2016^22^; 57; Retro; Moderate ROB | Treated with RP with either pre-op PSA >20, pT3 or positive margins, or pathologic Gleason score ≥ 8; Bx, RP; RP; 1987–2008 | CAPRA-S | HR = 1.64 (1.11, 2.42)
Ross, 2016a ^59^; 422; Retro; Moderate ROB | Adverse pathology patients treated with RP and adjuvant RT, RT for minimal PSA, RT with higher PSA recurrence compared to patients with no RT; 1990–2010 | CAPRA-S, treatment (adjuvant radiation vs minimal residual disease salvage radiation, salvage radiation, no radiation) | HR = 1.28 (1.08, 1.52)
Ross, 2016b^61^; 260; Retro; Moderate ROB | Treated with RP with CAPRA-S score ≥ 3, pathologic Gleason score ≥ 7, and post-RP PSA nadir < 0.2; RP; RP; 1992–2010 | CAPRA-S | HR = 1.32 (1.17, 1.51)
Ross, 2016b^61^; 260; Retro; Moderate ROB | Treated with RP with CAPRA-S score ≥ 3, pathologic Gleason score ≥ 7, and post-RP PSA nadir < 0.2; RP; RP; 1992–2010 | CAPRA-S | AUC; Clinical features 0.77 (0.69, 0.85); Clinical features and test; 0.87 (0.77, 0.94)
Den, 2015^63^; 188; Retro; Low ROB | pT3 and/or positive surgical margins at RP treated with PORT; RP; RP+RT; 1990–2009 | CAPRA-S score | HR = 1.69 (1.24, 2.31)
Den, 2015^63^; 188; Retro; Low ROB | pT3 and/or positive surgical margins at RP treated with PORT; RP; RP+RT; 1990–2009 | CAPRA-S score | AUC; Clinical features 0.66 (0.56, 0.78); Clinical features and test; 0.85 (0.79, 0.93)
Howard, 2020^44^; 548; Retro; Low ROB | Treated with RP with either pT3a, positive margins, SVI, or had PORT; RP; RP with or without RT; 1989–2016 | Age at RP; CAPRA-S; High vs low/intermediate; Race: Black vs non-Black | Decipher; Intermediate vs low; HR = 6.51 (2.33, 21.8); Decipher; High vs low; HR = 9.60 (3.51,32.0)
Howard, 2020^44^; 548; Retro; Low ROB | Treated with RP with either pT3a, positive margins, SVI, or had PORT; RP; RP with or without RT; 1989–2016 | | AUC; Clinical features 0.72 (0.57, 0.85); Clinical features and test; 0.77 (0.64, 0.90)
Spratt, 2018a^52^; 150; Retro; Moderate ROB | Treated with RP with persistently detectable PSA; RP; RP; 1990–2015 | CAPRA-S; Post-operative PSA | Decipher; High vs low/intermediate; HR = 7.12 (2.64, 21.7)
Spratt, 2018a^52^; 150; Retro; Moderate ROB | Treated with RP with persistently detectable PSA; RP; RP; 1990–2015 | Pre-op PSA; Pathologic grade groups; 4 and 5, 3 vs. 1 and 2; Positive margins; Pathologic T stage; T3b and T4, T3a vs T2 | Decipher; High vs low/intermediate; HR = 5.61 (1.48, 22.7)
Spratt, 2018a^52^; 150; Retro; Moderate ROB | Treated with RP with persistently detectable PSA; RP; RP; 1990–2015 | CAPRA-S | AUC; Clinical features 0.69 (0.41, 0.89); Clinical features and test; 0.83 (0.70, 1.00)
Klein, 2015^64^; 169; RCC; Low ROB | Treated with RP with either pre-op PSA >20 pT3 or positive margins or Gleason score ≥ 8 and pN0, undetectable post-RP PSA, no neoadjuvant or adjuvant therapy, and a minimum of 5-yr follow-up for those who remained metastasis free; RP; RP; 1987–2008 | CAPRA-S | OR = 1.43 (1.07, 1.91)
Klein, 2015^64^; 169; RCC; Low ROB | | CAPRA-S | AUC; Clinical features 0.72 (0.6, 0.84); Clinical features and test; 0.78 (0.68, 0.89)
Spratt, 2018b^19^; 235; Retro; High ROB | PSA <200, cT1c-T3b, and cN0; Biopsy; RP or RT with or without ADT; 1995–2005 | Treatment, stratified by institution | Clinical-genomic risk grouping; Intermediate vs low; HR = 22.3 (2.9, 2,863.8)
Spratt, 2018b^19^; 235; Retro; High ROB | PSA <200, cT1c-T3b, and cN0; Biopsy; RP or RT with or without ADT; 1995–2005 | Treatment, stratified by institution | Clinical-genomic risk grouping; High vs low; HR = 61.6 (8.1, 7914.9)
Spratt, 2018b^19^; 235; Retro; High ROB | PSA <200, cT1c-T3b, and cN0; Biopsy; RP or RT with or without ADT; 1995–2005 | 6 tier clinical-genomic risk groups (10 years) | AUC; 0.84 (0.61, 0.93)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed; Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA; T Stage; Grade group | AUC; Clinical features 0.55 (0.5, 0.6); Test only; 0.74 (0.69, 0.78)
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2005 | NCCN; High vs low and very low; Intermediate vs low and very low | HR = 2.34 (1.42, 3.86)
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2005 | CAPRA | HR = 2.63 (1.58, 4.36)
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2005 | NCCN | AUC; Clinical features 0.66 (NR); Clinical features and test; 0.75 (NR)
Brooks, 2021^39^; 428; Retro; Low ROB | Treated with RP; RP; RP; 1987–2004 | Log2(PSA) Grade; high vs low; T Stage; high vs low | HR = 2.24 (1.49, 3.53)
Brooks, 2021^39^; 428; Retro; Low ROB | Treated with RP; RP; RP; 1987–2004 | Log2(PSA); High grade; High T stage | AUC; Clinical features 0.772 (NR); Clinical features and test; 0.824 (NR)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed; Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA; T Stage; Grade group | AUC; Clinical features 0.55 (0.5, 0.6); Test only; 0.65 (0.6, 0.7)
Prolaris
Canter, 2020^46^; 1062; Retro; Low ROB | Patients from 4 different institutions; Biopsy or RP; RP or RT with or without ADT; 1994–2006 | CAPRA, Treatment; Institutional cohort | HR = 2.21 (1.64, 2.98)
Canter, 2020^46^; 1062; Retro; Low ROB | Patients from 4 different institutions; Biopsy or RP; RP or RT with or without ADT; 1994–2006 | Treatment; Institutional cohort | CCR score; (CAPRA and Prolaris scores); HR = 3.63 (2.60, 5.05)
Canter, 2020^46^; 1062; Retro; Low ROB | Patients from 4 different institutions; Biopsy or RP; RP or RT with or without ADT; 1994–2006 | CAPRA | AUC; Clinical features 0.857 (NR); CCR; 0.894 (NR)
Bishoff, 2014^71^; 582; Retro; High ROB | Clinically localize, treated with RP; Biopsy, RP; RP; 1994–2006 | Log(1 + PSA); Gleason Score; 7,>7 vs <7; Percent positive cores; Adjuvant treatment; Age at diagnosis | HR = 4.19 (2.08, 8.45)
Canter, 2019^48^; 767; Retro; Low ROB | Prostate adenocarcinoma with PSA < 100, cT1-T3M0 that did not undergo TURP, cryosurgery, or laser ablation; Biopsy; RP, RT with or without ADT, ADT or none; 2006–2011 | CAPRA; Ancestry: Black vs non-Black; Primary treatment | HR = 2.03 (1.47, 2.78)
Canter, 2019^48^; 767; Retro; Low ROB | Prostate adenocarcinoma with PSA < 100, cT1-T3M0 that did not undergo TURP, cryosurgery, or laser ablation; Biopsy; RP, RT with or without ADT, ADT or none; 2006–2011 | CAPRA | AUC; Clinical features 0.88 (NR); Clinical features and test; 0.90 (NR)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed; Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA; Stage; Grade group | AUC; Clinical features 0.55 (0.5, 0.6); Test only; 0.73 (0.69, 0.78)

Abbreviations. ADT=androgen deprivation therapy; AJCC=American Joint Committee on Cancer; AUC=area under the curve; BCR=biochemical recurrence; CAPRA=Cancer of the Prostate Risk Assessment; ECE=extra-capsular extension; NCCN=National Comprehensive Cancer Network; HR=hazard ratio; PLND=pelvic lymph node dissection; PORT=post-operative radiation therapy; PSA=prostate-specific antigen; RP=radical prostatectomy; RT=radiation therapy; SVI=seminal vesicle involvement.

### Prostate-cancer-specific Mortality

#### Decipher

Five studies (3 low ROB,^41,44,66^ 1 moderate ROB,^54^ and 1 high ROB^40^) addressed the impact of the Decipher score on the prediction of prostate-cancer-specific mortality in addition to standard clinical or pathologic features.^40,41,44,54,66^ Two low ROB studies (N = 538) examined the additive benefit of Decipher with this outcome among patients post-prostatectomy and reported similar HRs of 1.81 (95% CI [1.48, 2.25]) and 1.39 (95% CI [1.20, 1.63]) (Figure 12 and Table 12). The third low ROB study was an exclusively Veteran cohort (N = 548) who underwent prostatectomy between 1989 and 2016. In models with CAPRA-S and race (Black vs non-Black), Decipher was rounded to have HRs of 25.5 (95% CI [2.84, 3,365]) and 56.0 (95% CI [6.82, 7,297]) for intermediate and high risk Decipher scores, compared to low risk, respectively.^44^ Of note, this low ROB study had an event rate of 12 for PCSM, leading to large CIs. This corresponded with a non-significant increase in AUC from 0.81 (95% CI [0.63, 0.95]) with CAPRA-S alone to 0.856 (95% CI [0.71, 0.98]) with CAPRA-S and Decipher (Figure 13). Finally, the ancillary study of RTOG 9601 discussed previously assessed prostate-cancer-specific mortality in men following prostatectomy. Models including both clinical and pathologic features demonstrated HRs of 1.39 (95% CI [1.20, 1.63]) and 2.94 (95% CI [1.57, 5.81]) with Decipher as a continuous and categorical variable (high or intermediate versus low), respectively.^41^ Of note, the study by Feng et al also showed the prognostic ability of the Decipher score for overall survival, with an HR of 1.17 (95% CI [1.06, 1.29]) in a model similar to those for prostate-cancer-specific mortality.^41^

The 1 moderate ROB study included 561 men who underwent prostatectomy (113 of whom were Veterans). In a model including CAPRA-S, increases of 0.1 unit in Decipher score had a greater odds of prostate-cancer-specific mortality (OR = 1.34, 95% CI [1.2, 1.5]).^54^ This was associated with a non-significant increase in AUC from 0.73 (95% CI [0.68, 0.78]) to 0.76 (95% CI [0.71, 0.82]) when incorporating Decipher with CAPRA-S. Concerns for potential ROB in this study were moderate for both study participation by eligible individuals and prognostic factor measurement.

In the same high ROB study by Lehto et al discussed above which evaluated AUCs for all 3 tests, the AUC for prostate-cancer-specific mortality did significantly increase from 0.55 (95% CI [0.49, 0.6]) with clinical features to 0.72 (95% CI [0.66, 0.77]) with inclusion of the Decipher score.^40^

#### Oncotype

Three studies, all retrospective (2 low ROB and 1 high ROB) and in men who underwent prostatectomy, evaluated the Oncotype score’s additive prognostic value for prostate-cancer-specific mortality.^39,40,53^ Each showed an increase in the AUC: from 0.71 with NCCN classification alone to 0.81 with the addition of the Oncotype score in Van den Eeden et al,^53^ from 0.762 to 0.822 (95% CIs not reported) in Brooks et al,^39^ and from 0.55 (95% CI [0.49, 0.6]) to 0.69 (95% CI [0.63, 0.74]) with the addition of the Oncotype score to models with clinical features in the high ROB study by Lehto et al.^40^ The HRs for prostate-cancer-specific mortality were reported in 2 of the publications, 2.69 (95% CI [1.50, 4.82]) in a model with NCCN in Van den Eeden et al^53^ and 2.30 (95% CI [1.45, 4.36]) in a model with clinical features in Brooks et al.^39^

#### Prolaris

Four studies assessed the additive prognostic value for prostate-cancer-specific mortality by the Prolaris score or CCP.^4,40,62,69^ Three Prolaris studies (N = 1,675) contributed to a meta-analysis of the additive prognostic effect and reported a summary HR of 1.72 (95% CI [1.58, 1.87]; 95% PI [1.58, 1.87]). Three of these were by Cuzick et al.^4,62,69^ The first was a low ROB study published in 2011, and included a cohort of 337 men diagnosed by TURP; within this cohort the CCP score had an HR for prostate-cancer-specific mortality of 2.57 (95% CI [1.93, 3.43]) when included in a model with clinical features.^4^ The second moderate ROB study by Cuzick et al, from 2012, evaluated CCP scores derived from biopsy specimens in a similar manner to the first, showing an HR of 1.65 (95% CI [1.31, 2.09]) for prostate-cancer-specific mortality in a model with clinical features.^69^ The final Cuzick et al report from 2015 (low ROB), in a separate cohort of patients with biopsy specimens from the 2012 manuscript, demonstrated an HR of 1.76 (95% CI [1.44, 2.14]) in a model with CAPRA. In addition, the AUC was reported to increase from 0.74 to 0.78 with the addition of the CCP score to the CAPRA score.^62^ A significant increase in AUC was also reported by Lehto et al, from 0.55 (95% [CI 0.49, 0.60]) to 0.66 (95% CI [0.61, 0.74]), with the addition of the CCP score to clinical features in a cohort of 160 men who underwent prostatectomy.^40^

Figure 12 Hazard Ratio Forest Plot for Prostate-cancer-specific Mortality by Test Type (Decipher, Oncotype, Prolaris)^a^ a Notes. Model includes age (≥65 vs <65), Black men vs non Black men, Gleason score (8–10 vs ≤7), T stage (pT3 vs pT2), PSA at trial entry, positive surgical margins, PSA nadir status (non-nadir vs nadir <0.5), ADT vs placebo.

Figure 13 C-statistic Forest Plot for Prostate-cancer-specific Mortality by Test Type (Decipher, Oncotype)

Notes. ^a^ Model includes PSA, T stage, Gleason group, Oncotype.

Table 12 Studies Reporting Prostate-cancer-specific Mortality

Study; Total N; Design; ROB | Clinical Characteristics; Tissue Source; Treatment; Study Duration | Model Variables | Results (95% CI)
Decipher
Karnes, 2018^54^; 561; Retro; Moderate ROB | Treated with RP with pT3, pN1, positive margins, or Gleason score >7; RP; RP; 1987–2010 | CAPRA-S | OR = 1.34 (1.20, 1.50)
Karnes, 2018^54^; 561; Retro; Moderate ROB | Treated with RP with pT3, pN1, positive margins, or Gleason score >7; RP; RP; 1987–2010 | CAPRA-S | AUC Clinical features; 0.73 (0.68, 0.78); Clinical features and test; 0.76 (0.71, 0.82)
Feng, 2021^41^; 351; Ancillary study of a phase III trial; Low ROB | Treated with RP and PLND with pT2N0M0 and positive surgical margins or pT3N0M0, and PSA of 0.2–4 at least 8 weeks after surgery; KPS ≥ 80; No prior therapy other than short period ADT; No liver disease; Life expectancy of ≥ 10 years; RP; RP and RT ±2 years ADT; 1998–2003 | Age: ≥ 65 vs <65; Race: Black vs non-Black; Gleason score: 8–10 vs ≤7; T stage:; pT3 vs pT2; PSA at trial entry; Positive surgical margins; PSA nadir status; Non-nadir vs nadir (<0.5); ADT vs placebo | HR = 1.39 (1.20, 1.63)
Feng, 2021^41^; 351; Ancillary study of a phase III trial; Low ROB | | Age: ≥65 vs <65; Race: Black vs non-Black; Gleason score: 8–10 vs ≤7; T stage:; pT3 vs pT2; PSA at trial entry; Positive surgical margins; PSA nadir status; Non-nadir vs nadir (<0.5); ADT vs placebo | Decipher; High/intermediate vs low; HR = 2.94 (1.57, 5.81)
Cooperberg, 2015^66^; 187; Retro; Low ROB | Treated with RP with pre-op PSA >20, Gleason score ≥ 8 or pT3b without neo-adjuvant therapy, metastatic disease or lack of a PSA nadir post-RP; RP; RP; 2000–2006 | CAPRA-S; Adjuvant therapy (RT or ADT) | HR = 1.81 (1.48, 2.25)
Cooperberg, 2015^66^; 187; Retro; Low ROB | Treated with RP with pre-op PSA >20, Gleason score ≥ 8 or pT3b without neo-adjuvant therapy, metastatic disease or lack of a PSA nadir post-RP; RP; RP; 2000–2006 | CAPRA-S | AUC; Clinical features; 0.75 (0.65, 0.84); Clinical features and test; 0.78 (NR)
Howard, 2020^44^; 548; Retro; Low ROB | Treated with RP with either pT3a, positive margins, SVI, or had PORT; RP; RP with or without RT; 1989–2016 | Age at RP; CAPRA-S; High vs low/intermediate; Race: Black vs non-Black | Decipher; Intermediate vs low; HR = 25.5 (2.84, 3365); Decipher; High vs low; HR = 56.0 (6.82, 7297)
Howard, 2020^44^; 548; Retro; Low ROB | Treated with RP with either pT3a, positive margins, SVI, or had PORT; RP; RP with or without RT; 1989–2016 | CAPRA-S | AUC; Clinical features; 0.81 (0.63, 0.95); Clinical features and test 0.86 (0.71, 0.98)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA; T Stage; Grade group | AUC; Clinical features; 0.55 (0.49, 0.6); Test only; 0.72 (0.66, 0.77)
Oncotype
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2005 | NCCN | HR = 2.69 (1.50, 4.82)
Van Den Eeden, 2018^53^; 259; Retro; Low ROB | RP within 12 months of diagnosis; Biopsy; RP; 1995–2005 | NCCN | AUC; Clinical features; 0.71 (NR); Clinical features and test; 0.81(NR)
Brooks, 2021^39^; 428; Retro; Low ROB | Treated with RP; RP; RP; 1987–2004 | Log2(PSA) Grade; high vs low; T stage; high vs low | HR = 2.30 (1.45, 4.36)
Brooks, 2021^39^; 428; Retro; Low ROB | Treated with RP; RP; RP; 1987–2004 | Log2(PSA); High grade; High T stage | AUC; Clinical features; 0.762 (NR); Clinical features and test; 0.822 (NR)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA; T stage; Grade group | AUC; Clinical features; 0.55 (0.49, 0.6); Test only; 0.69 (0.63, 0.74)
Prolaris
Cuzick 2015^62^; 989; Retro; Low ROB | Clinically localized, with age <76 and excluding metastatic disease or PSA >100 or treatment within 6 months of diagnosis; Biopsy; NR; 1990–2003 | CAPRA | HR = 1.76 (1.44, 2.14)
Cuzick 2015^62^; 989; Retro; Low ROB | Clinically localized, with age <76 and excluding metastatic disease or PSA >100 or treatment within 6 months of diagnosis; Biopsy; NR; 1990–2003 | CAPRA | AUC; Clinical features; 0.74 (NR); Clinical features and test; 0.78 (NR)
Cuzick, 2012^69^; 349; Retro; Moderate ROB | Clinically localized, with age <76 and excluding metastatic disease or treatment within 6 months of diagnosis; Biopsy; NR; 1990–1996 | Log(1+PSA); Gleason score; <7, >7 vs 7 | HR = 1.65 (1.31,2.09)
Cuzick, 2011^4^; 366; Retro; Low ROB | RP without neoadjuvant therapy; RP; RP; 1985–1995 | Log(1+baseline PSA); Gleason score; 7,>7 vs <7 | HR = 1.74 (1.39, 2.17)
Canter, 2019^48^; 767; Retro; Low ROB | Prostate adenocarcinoma with PSA < 100, cT1-T3M0 that did not undergo TURP, cryosurgery, or laser ablation; Biopsy; RP, RT with or without ADT, ADT or none; 2006–2011 | CAPRA | AUC; Clinical features 0.91 (NR); Clinical features and test 0.94 (NR)
Lehto, 2021^40^; 160; RCC; High ROB | Treated with RP with Gleason 3+4, 4+3, 4+4 and AJCC 8^th^ ed Stage II-II without neo-adjuvant treatment; RP; RP; 1992–2015 | PSA Stage; Grade group | AUC; Clinical features; 0.55 (0.49, 0.6); Test only; 0.66 (0.61, 0.74)

### Other Reported Outcomes

#### Decipher

Three additional studies assessed alternative or composite endpoints with Decipher testing (Table 13).^37,38,57,60^ A low ROB study of 241 patients treated with definitive radiation or prostatectomy from the Decipher GRID registry were evaluated for time-to-treatment failure defined as biochemical recurrence or initiation of salvage therapy after definitive treatment.^38^ The HR for time to treatment failure was 2.98 (95% CI [1.22, 7.29]) in a model containing NCCN risk classification and other clinical features. Of interest, Vince et al is the only study addressing KQ3 that includes patients undergoing genomic classifier testing at the time of diagnosis and not a cohort aggregated from banked tissue specimens.^38^

In the low ROB study by Glass et al discussed previously, clinical recurrence was assessed, and although noted to be distinct from biochemical recurrence, was not clearly defined.^60^ Regardless, in a model with CAPRA-S Decipher did show a significant HR for clinical recurrence of 1.48 (95% CI [1.09, 2.01]) with a non-significant increase in the AUC from 0.73 (95% CI [0.49, 0.95]) for clinical features alone to 0.84 (95% CI [0.7, 0.96]) with clinical features and the Decipher score. A second, moderate ROB study also assessed the time to clinical recurrence with Decipher.^57^ In this study, time to clinical recurrence was a composite endpoint of biopsy proven prostate bed recurrence or development of regional or distant metastatic disease on imaging. Among 512 men (including 104 Veterans) who had undergone prostatectomy, Decipher as a categorical variable was found to have HRs of 1.40 (95% [CI 0.7, 2.74]) and 2.93 (95% CI [1.58, 5.55]) for intermediate and high risk Decipher scores, respectively, in a model with clinical features. This corresponded to a non-significant increase in the AUC from 0.79 (95% CI [0.73, 0.86]) to 0.85 (95% CI [0.80, 0.89]) when adding in Decipher results.

Last, time to secondary therapy was reported in a moderate ROB study among patients treated with radical prostatectomy.^37^ In a model including age, PSA, pathological grade group, positive surgical margins, extraprostatic extension, and seminal vesicle invasion, the HR for Decipher was 1.46 (1.34 to 1.66).

#### Oncotype

No studies with Oncotype were identified that evaluated endpoints other than BCR, metastases, or prostate-cancer-specific mortality.

#### Prolaris

One low ROB retrospective study employing Prolaris among 424 patients treated with radical prostatectomy also reported a composite endpoint of metastasis or prostate-cancer-specific mortality.^50^ In a model including CAPRA-S and CCP scores, the HR for Prolaris was 2.15 (95% CI [1.36, 3.39]) for this composite endpoint.

Table 13 Studies Reporting Other Outcomes

Study; Total N; Design; Risk of Bias (ROB) | Clinical Characteristics; Tissue Source; Treatment; Study Duration | Model Variables | Results
Decipher
Time to Treatment Failure
Vince, 2021^38^; 241; Prospective; Low ROB | Clinically localized, underwent testing as part of routine clinical care and were able to be matched with Decipher GRID registry; Biopsy; RP or RT; 2015–2019 | NCCN; Age; Log(PSA); Log(prostate volume); BMI; Percent positive cores | HR = 2.98 (1.22 to 7.29)
Time to Secondary Therapy
Shahait, 2021^37^; 398; Prospective; Moderate ROB | T reated with RP; RP; RP; 2013–2018 | Age; Log2(pre-op PSA); Pathological GG; 4–5 vs 1–3; Positive surgical margins; EPE; SVI | HR = 1.49 (1.34 to 1.66)
Time to Clinical Recurrence
Dalela, 2017^57^; 512; Retrospective; Moderate ROB | Treated with RP with ≥pT3a, positive margins, and/or lymph node invasion who achieved a PSA nadir after RP; RP; RP; 1990–2010 | Log2(PSA); T stage: pT3a, pT3b-4 vs pT2; Pathologic Gleason score: 8–10 vs ≤7; Lymph node invasion; Surgical margins; Adjuvant RT; Adjuvant ADT | Decipher; Intermediate vs low risk; HR = 1.40 (0.7, 2.74); High vs low risk; HR = 2.93 (1.58 to 5.55)
Dalela, 2017^57^; 512; Retrospective; Moderate ROB | Treated with RP with ≥pT3a, positive margins, and/or lymph node invasion who achieved a PSA nadir after RP; RP; RP; 1990–2010 | Log2(PSA); T stage; pT3a, pT3b-4 vs pT2; Pathologic Gleason score: 8–10 vs ≤7; Lymph node invasion; Surgical margins; Adjuvant RT; Adjuvant ADT | AUC; Clinical features; 0.79 (0.73 to 0.86); Clinical features and test; 0.85 (0.8 to 0.89)
Glass, 2016^60^; 224; Retrospective; Low ROB | RP with high-risk pre-op features (PSA > 20 or GS ≥ 8) pT3, or +SM; RP; RP; 2001–2013 | CAPRA-S; Age at diagnosis | HR = 1.48 (1.09 to 2.01)
Glass, 2016^60^; 224; Retrospective; Low ROB | RP with high-risk pre-op features (PSA > 20 or GS ≥ 8) pT3, or +SM; RP; RP; 2001–2013 | CAPRA-S | AUC; Clinical features; 0.73 (0.49 to 0.95); Clinical features and test; 0.84 (0.7 to 0.96)
Oncotype (No Studies)
Prolaris
Metastasis or Prostate-cancer-specific Mortality
Leapman, 2018^50^; 424; Retrospective; Low ROB | Treated with RP; Biopsy; RP; Prior to 2017 | CAPRA-S | HR = 2.15 (1.36 to 3.39)
Leapman, 2018^50^; 424; Retrospective; Low ROB | Treated with RP; Biopsy; RP; Prior to 2017 | CAPRA-S | AUC; Clinical features and test; 0.81 (NR)