# METHODS

## TOPIC DEVELOPMENT

This topic was developed at the request of the National Radiation Oncology Program and the National Oncology Prostate Cancer Clinical Pathways team. Findings from this review will be used to inform the multidisciplinary national clinical pathway for prostate cancer used by all providers who diagnose, treat, and manage prostate cancer patients in the VA.

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Among individuals with localized prostate cancer who are considering first-line definitive treatment, does the addition of a tissue-based genomic test to existing clinical risk models impact risk classification?
KQ2 Does tissue-based genomic testing impact the choice of treatment intensity or harms:
  A. Among individuals with localized prostate cancer before first-line definitive treatment?
  B. Among individuals who have undergone radical prostatectomy?
KQ3 Among patients with localized prostate cancer, what is the incremental prognostic effect of tissue-based genomic tests beyond existing prognostic clinical features on key clinical outcomes (eg, biochemical recurrence-free survival, metastases-free survival) following definitive treatment?

The conceptual framework developed to guide the approach to this review is in Appendix C.

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42022347950).

## DATA SOURCES AND SEARCHES

The MEDLINE (via Ovid), Embase (via Elsevier), and Web of Science (via Clarivate) databases were searched from 2010 to the present using a combination of database-specific controlled vocabulary terms and keywords searched in the titles and abstracts related to prostate cancer and genomic tests. An experienced medical librarian devised and conducted the search, with input on keywords from the other authors. The search strategies were peer reviewed by another librarian using a modified PRESS checklist.^9^ The original searches were conducted on April 20, 2022. Case reports, editorials, letters, comments, and conference abstracts were excluded from the search, as were animal-only studies. The full, reproducible search strategies are in Appendix B. In addition, we hand-searched previous systematic reviews conducted on this or a related topic for potential included studies.

## STUDY SELECTION

### Eligibility Criteria

Studies identified through our primary search were classified independently based on title and abstract by 2 investigators for relevance to the KQs from our a priori established eligibility criteria. All citations classified for inclusion by at least 1 investigator were reviewed at the full-text review level. The citations designated for exclusion by 1 investigator at the title and abstract level underwent screening by a second investigator. If both investigators agreed on exclusion, the study was excluded. All articles meeting eligibility criteria were included for data abstraction. All results were tracked in an electronic database (for referencing, EndNote, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR, Evidence Partners Inc., Manotick, ON, Canada).

Table 1 describes the study eligibility criteria organized by PICOTS elements (population, intervention, comparator, outcome, timing, setting) and other criteria such as study design, language, and publication type. Note that while the Oncotype genomic classifier test was acquired by MDxHealth and is now named Genomic Prostate Score (GPS), we use the name Oncotype throughout this report because most of the articles reviewed used the former name.

Table 1 Eligibility Criteria

| Inclusion | Exclusion
Population | KQ1, 2A: Patients with localized prostate cancer who are seeking first-line definitive treatment; KQ2B: Patients who have localized prostate cancer who have undergone radical prostatectomy considering post-surgical treatment intensity; KQ3: Patients who have localized prostate cancer who have undergone definitive radiation or surgery | Patients with metastatic (de novo or recurrent) prostate cancer with either distant or non-regional nodal metastases
Index prognostic factor | Tissue-based, multigene expression classifiers, specifically:; - Decipher; - Oncotype (now known as genomic prostate score or GPS); - Prolaris (eg, cell cycle progression [CCP] molecular score); Tissue upon which testing is run can be from a diagnostic biopsy or prostatectomy; Diagnostic test does not need to be run at the time of tissue acquisition | - Germline genetic testing; - Next-generation sequencing; - Other gene signatures (eg, Post-Operative Radiation Therapy Outcomes Score [PORTOS])
Comparator prognostic factors | Clinical feature-based prediction models (eg, AUA/NCCN, CAPRA-S); Prediction models must include the following minimum core set of clinical features: PSA, Gleason score, and clinical tumor (T) stage | Prognostic factors not meeting the minimal core set
Outcomes | KQ1: Changes in risk classification or reclassification, difference in classification; KQ2: Proportion choosing active surveillance, change in management/treatment decision-making, addition of ADT to definitive radiation, receipt of adjuvant radiation with or without ADT harms (eg, complications from unnecessary treatment); KQ3^a^: Biochemical recurrence-free survival, metastasis-free survival, prostate-cancer-specific mortality, overall survival, time-on surveillance | - Adverse pathology at prostatectomy; - Patient experience of treatment decision (eg, decision conflict)
Timing | [underlined: Time test is measured]: At any time point in clinical management but run on tissue obtained at diagnostic biopsy or prostatectomy; [underlined: Time outcomes assessed]:; - KQ1: At the time of first-line definitive treatment determination; - KQ2: At the time of relevant treatment decision (intensity) and at least 12 months after receipt of treatment (harms); - KQ3: At least 3 years after test measurement
Setting | Any setting
Study design | Randomized trials (including pilot studies), pre-post studies, retrospective/prospective cohort studies (including observational data drawn from randomized trials), case-control studies, individual meta-analysis | - Case studies/series; - Systematic reviews
Publication types | Full publication in a peer-reviewed journal | Letters, opinion pieces, editorials, reviews, dissertations, meeting abstracts, protocols without results
Years | 2010 to April 20, 2022

Notes.

a Given the relatively recent development of these tests, longer term clinical outcomes data, such as overall survival, may not be available. As such, we also considered intermediate outcomes such as biochemical recurrence and metastases-free survival.

Abbreviations. AUA=American Urological Association; KQ=key question; PSA=prostate-specific antigen.

## DATA ABSTRACTION AND ASSESSMENT

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. We extracted data elements from included studies including descriptors to assess applicability, quality elements, population characteristics, intervention details, and outcomes including prognostic effect estimates and adverse events. Our extraction process was guided by CHARMS-PF (the checklist for critical appraisal and data extraction for systematic reviews of prognostic factor studies).^10^ Key characteristics abstracted included participant descriptors (eg, age, race, clinical status), test type (eg, Decipher, Prolaris, Oncotype), comparator, prognostic effect estimates, and outcomes. We attempted to identify when a cohort of patients from an individual institution was included in multiple analyses. When identified, we prioritized data from the larger or more inclusive cohort analysis.

In accordance with our a priori plan, we prioritized randomized trials, prospective cohort studies, cohorts with longer follow-up duration (>5 years), nested case-control studies, and validation or confirmatory studies over training cohorts or data used to establish a test, given the volume of identified literature. While cost outcomes were not relevant to the determination of eligibility, we had an a priori interest in cost outcomes related to the use of genomic classifier tests in the identified studies and these outcomes were collected when available.

For risk of bias (ROB) assessment, we selected the appropriate tool relevant to the included study design. For studies solely or primarily relevant to KQ3 or prognostic outcomes, we used QUIPS because it is a validated tool to assess quality in prognostic factor studies.^11^ Domains included in QUIPS include study participation, study attrition, prognostic factor measurement, outcome measurement, adjustment for other prognostic factors, and statistical analysis and reporting. Based on a previously published approach, any study that was rated high in 1 or more domains or moderate for 3 or more was considered high ROB overall. Any study that was rated low ROB in all 6 domains or up to 1 moderate ROB was considered low ROB overall.^12^ Studies that did not meet either of those conditions were considered moderate ROB overall. For KQ1 and KQ2, studies that did not otherwise address KQ3 as a prognostic outcomes study, we used ROB-2^13^ for randomized trials and ROBINS-I for observational designs.^14^ These criteria included adequacy of randomization and allocation concealment, comparability of groups at baseline, blinding, completeness of follow-up and differential loss to follow-up, whether incomplete data were addressed appropriately, validity of outcome measures, protection against contamination, selective outcomes reporting, and conflict of interest. We assigned a summary ROB rating to individual studies.

We paid attention to particular areas of potential bias among identified studies including the following: (1) exclusion of patient data due to inadequate tissue or incalculable test score beyond 20% to 30%, which we considered average sample loss; (2) evidence that tests were run by a lab other than the commercial lab for the specific test, as the tests themselves are proprietary and a non-commercial lab would not be able to provide the equivalent testing results; (3) inadequate adjustment for basic clinical features considered standard for clinical risk assessment, and (4) clarity and consistency in the selection of patient populations for analysis, especially when data were drawn from multiple health care systems or clinics.

We completed ROB in duplicate for 25% of included studies. Because we found sufficient agreement, the remaining included studies were assessed for ROB by 1 investigator and overread by a second given the volume of included studies for observational designs. Lastly, we audited ROB assessments for consistency across the included studies. These criteria included adequacy of randomization and allocation concealment, comparability of groups at baseline, blinding, completeness of follow-up and differential loss to follow-up, whether incomplete data were addressed appropriately, validity of outcome measures, protection against contamination, selective outcomes reporting, and conflict of interest. We assigned a summary ROB score to individual studies. We completed ROB in duplicate for 25% of included studies. Because we found sufficient agreement, the remaining included studies were assessed for ROB by 1 investigator and over-read by a second given the volume of included studies.

## SYNTHESIS

We summarized the primary literature using data abstracted from eligible studies. Summary tables describe key study characteristics of the primary studies (eg, study design, patient demographics, and genomic test). We determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary prognostic effects; feasibility decisions were based on the volume of relevant literature, types of effect measures reported, and completeness of results. We also considered similarity in patient treatment status (before or after first-line definitive treatment), test studied, follow-up duration, and definitions of risk classifications. We did not combine outcomes across the 3 types of commercial genomic classifier tests, as each test evaluates the expression profile of distinct gene panels that differ across the tests, details of which are not publicly available, and therefore cannot be determined to be equivalent. Conceptual consistency was primarily based on clinical contextualization and consideration for which types of patient cohorts were similar enough for a combined analysis (eg, those who had received or not received definitive initial treatment for prostate cancer). For each key outcome, we reviewed operationalized definitions of the outcome variable and combined those that were sufficiently conceptually similar after discussion with clinical experts on our team (MB, DC).

For KQ1, we prioritized data reported at the individual level (ie, reporting of specific number or percentage of patients that changed from 1 specific risk level to another risk level). We summarized no change, higher, and lower reclassification across reported levels (eg, % changed from low to favorable intermediate plus, % changed from unfavorable intermediate to high for reclassification to a higher level). When individual-level data were not provided, we report summary % reclassification as given in the primary article. For KQ2, we similarly categorized treatment intensification versus de-intensification based on how it was reported by the included studies.

For KQ 3, we considered a minimum set of established prognostic factors (ie, PSA, Gleason score, and clinical tumor [T] stage) for adequate adjustment. However, some otherwise eligible studies did not include T stage as a component of the regression model. Studies were not excluded for this reason. Because the genomic classifier tests of interest can be reported as both a continuous variable and a categorical variable, we report both. We only aggregated outcomes when there were at least 3 studies with the same outcome, based on the rationale that 2 studies do not provide adequate evidence for summary effects. We grouped outcomes by time point of outcome measurement (eg, 3–5 years after test measurement vs 6–10 years) due to the current understanding of the natural history of prostate cancer. Specifically, we did not combine discrimination statistics (eg, AUC, c-index) at 5 and 10 years, as the natural history of prostate cancer is slow and there is no clear existence of a natural plateau for outcomes that would support combining such data. For time-to-metastasis or metastasis-free survival, we combined studies defining this outcome by distant and/or regional metastases. This decision was driven by the recognition that while the location of metastases can drive treatment decisions, attention to the location of metastases has evolved over time, including during the time span of many of the included studies. We have noted the definitions for key outcomes in our study characteristics table (Appendix E).

For survival and other time-to-event outcomes, we abstracted hazard ratios and corresponding 95% confidence intervals (CIs). We also abstracted calibration (eg, O:E ratio) and discrimination (eg, c-statistic, AUC) statistics for models with and without the addition of a genomic classifier.

Given the KQs guiding this review, we only abstracted adjusted prognostic effect estimates with the most adjusted analyses prioritized.

When studies reported multiple models using different approaches to adjusting for clinical risk factors (eg, NCCN vs CAPRA risk stratification models, individual clinical risk factors), we prioritized the use of models as follows:

- For patient cohorts with an intact prostate and who had not received definitive therapy, we prioritized models using NCCN risk categorization, followed by CAPRA, and then individual clinical features.
- For patients who received radical prostatectomy, we prioritized CAPRA-S, followed by models with individual clinical risk factors.

Random-effects models were used for meta-analyses, and for analyses with fewer than 20 studies, we used the Knapp-Hartung approach to better account for uncertainty in estimates of the amount of heterogeneity among studies.

We evaluated heterogeneity using visual inspection of forest plots and 95% prediction intervals. When prediction intervals encompassed values that substantially differed from the effect estimate (in magnitude, direction, or both), we concluded that there was substantial heterogeneity present. Potential sources of heterogeneity we planned to investigate included case-mix variation, study characteristics (eg, follow-up time), analytic approach, and risk of bias.

When a quantitative synthesis was not feasible, we summarized the data narratively. We gave more weight to the evidence from higher quality studies with more precise estimates of effect. A narrative synthesis focused on documenting and identifying patterns of effect of incremental benefit of genomic classifier tests after consideration of existing clinical prognostic factors. We analyzed potential reasons for inconsistency in prognostic effects across studies by evaluating differences in the study population, clinical status, comparator, and timing and definition of outcome variables.

Nominators for this review expressed an a priori interest in differences in the effect of these genomic classifier tests by key subpopulations, specifically race/ethnicity and risk classification at the time of genomic classifier test sample collection. Given that this is a patient-level characteristic, we sought to identify analyses conducted within the primary literature that identified effect modification (eg, subgroup analyses, regression model explanatory variables). We were unable to consider meta-regression to explore quantitative or qualitative interactions of prespecified, potential effect modifiers including duration of follow-up due to lack of individual patient data. In addition, we narratively considered the representation of subgroups within identified studies in comparison with the VA population.

We assessed certainty of evidence using GRADE with consideration of guidance around adaptation for prognostic studies.^15^ We limited GRADE ratings to outcomes for KQ3 due to the volume and comparability of relevant studies. In brief, this approach requires assessment of 4 domains: ROB, consistency, directness, and precision. Additional domains to be used when appropriate are dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. We assigned a summary rating of high, moderate, low, or very low strength of evidence based on consensus among 3 investigators (KG, MB, AG). We did not downgrade for observational study designs as suggested for prognostic GRADE assessment.^15^ Studies that included patient data from the 1980s or early 1990s were downgraded for indirectness because patients in these studies have limited comparability with patients receiving modern cancer screening and treatment.