# INTRODUCTION

Prostate cancer is the most common malignancy in men with an estimated 268,490 new cases in the United States in 2022, and approximately 70% of these patients presented with localized disease.^1^ Prostate cancer is also the most common malignancy seen within the Veterans Health Administration (VHA), accounting for approximately 12,500 new diagnoses per year.^2^ Risk stratification of these patients to help define prognosis and guide treatment has been traditionally based on clinical features including prostate specific antigen (PSA) level, tumor staging, and biopsy results.^3^ However, multiple options exist for treatment, and there is variability in patient outcomes not otherwise explained by currently recognized risk factors. To improve the determination of individual risk of adverse clinical outcomes, tissue-based genomic classifier tests have been developed. The goal of these tests is to refine the current clinically based classification schema and inform personalized recommendations for treatment intensity. Depending on the point during the clinical course of prostate cancer at which the genomic classifier test is obtained, it can guide treatment intensity—such as the decision to pursue active surveillance, surgery, or radiation with or without hormonal therapy—or the timing and extent of adjuvant treatment following prostatectomy. Ultimately, the hope is for these tests to inform patient-physician decision-making, improve patient outcomes, and reduce overtreatment.

Tissue-based genomic classifiers have been developed with the goal of refining prognosis and personalizing treatment intensity. Three of the currently commercially available genomic classifier tests are Decipher, Oncotype (formerly Oncotype DX GPS, hereafter referred to as Oncotype), and Prolaris (Appendix A). Each test provides a score based on the expression of an empirically derived panel of genes in a patient’s biopsy or prostatectomy specimen that can be used to estimate the risk of important clinical outcomes.^4–6^ While large prospective studies are underway to assess the use of at least 1 of these studies (Decipher) to guide treatment intensity,^7,8^ results are not likely to be available for a decade or more. In the meantime, a review of what is currently known about genomic classifier tests in localized prostate cancer is needed to inform interim guidance for clinical care.

This systematic review examines (1) whether adding Decipher, Oncotype, or Prolaris tests to existing clinical risk models changes a patient’s risk classification, (2) how the use of these tests impacts treatment choice and if use of these tests causes harm, and (3) what prognostic value is offered by these tests beyond existing clinical risk models. We also consider available evidence on associations between test results (ie, risk classifications) and patient-important clinical outcomes, particularly survival.