# APPENDIX G ONGOING STUDIES

Test; Trial Name (Short); Projected N | Full Trial Name | Objective | Study Design; Follow-up | Outcomes Measured | Status/Projected Completion
Prolaris; NCT03152448 (https://clinicaltrials.gov/ct2/show/NCT03152448); 1511; *VA based study | Prospective Prolaris Value and Efficacy (P-PROVE) | To measure the impact on first-line therapy of genomic testing of biopsy tissue from recently diagnosed treatment-naïve patients with early stage localized prostate cancer. | Prospective observational; 5 years | - Effect on treatment; - Biochemical recurrence; - Progression to interventional treatment | Terminated- “Myriad has sufficient data to do an analysis on the primary objective, durability, and has made the decision not to continue collecting data for the other study objectives.”
Decipher; NCT02783950 (https://clinicaltrials.gov/ct2/show/NCT02783950); 356 | Genomics in Michigan Impacting Observation or Radiation (G-MINOR) | To determine the impact of Decipher test results on adjuvant treatment decisions of high-risk post-RP patients with undetectable post-op prostate specific antigen (PSA) compared to clinical factors alone. | Parallel assignment Interventional; 5 years | - Number of participants that receive Adjuvant treatment; - Time to Adjuvant treatment; - Time to salvage treatment administration; - Time to Biochemical Recurrence; - Time to Metastatic disease; - Patient Reported Outcomes | Active, not recruiting
Decipher; NCT 02723734 (https://clinicaltrials.gov/ct2/show/NCT02723734); 240 | Validation Study on the Impact of Decipher^®^ Testing - VANDAAM Study (VANDAAM) | To determine whether a tumor test recently developed by GenomeDx Biosciences known as Decipher^®^ can predict aggressive prostate cancer with the same accuracy in Black men (AAM) as in non-Black men (NAAM). | Multisite, prospective validation Observational study; 2 years | - Two-year PSA failure rate | Active, not recruiting
Decipher; NCT05050084 (https://clinicaltrials.gov/ct2/show/NCT05050084); 2050 | Two Studies for Patients With Unfavorable Intermediate Risk Prostate Cancer Testing Less Intense Treatment for Patients With a Low Gene Risk Score and Testing a More Intense Treatment for Patients With a Higher Gene Risk Score | This phase III trial uses the Decipher risk score to guide intensification (for higher Decipher gene risk) or de-intensification (for low Decipher gene risk) of treatment to better match therapies to an individual patient’s cancer aggressiveness. | Parallel Assignment Interventional; 5 years | - Distant Metastasis (DM); - Metastasis-Free Survival (MFS); - Overall Survival; - Time to PSA Failure; - MFS including PET Imaging; - Locoregional Failure; - DM Including PET imaging; - Prostate Cancer-specific mortality; - Sexual and Hormonal Function related quality of life; - Fatigue; - Cognition; - Locoregional Progression; - Castrate-resistant prostate cancer; - Bowel and Urinary Function related quality of life; - Cardio-metabolic markers; - PSA Failure-free survival with non-castrate testosterone and no additional therapies; - Locoregional failure based upon either conventional or molecular imaging; - Health Utilities; - Time to testosterone recovery | Recruiting
Prolaris; NCT04404894 (https://clinicaltrials.gov/ct2/show/NCT04404894); 500 | Long-Term Prospective Registry in Prostate Cancer Patients From Diverse Urology Practice Settings Following Prolaris Testing | This registry will evaluate treatment selection for patients with newly diagnosed, localized prostate cancer following Prolaris testing. It will measure the proportion of men who initially select treatment with active surveillance, the time frame between active surveillance selection and any change in treatment, and clinical outcomes. | Prospective Observational; 10 years | - Active Surveillance Durability; Comorbidities; - Disease Progression; - Baseline Clinicopathologic Measures; - Proportion of men with prostate cancer who: (1) Meet NCCN hereditary high-risk criteria, (2) undergo and complete hereditary cancer genetic testing; and (3) are found to carry pathogenic variants in tested cancer-predisposition genes | Recruiting
All; NCT04396808 (https://clinicaltrials.gov/ct2/show/NCT04396808); 900 | Genomics in Michigan to Adjust Outcomes in Prostate cancer (G-MAJOR) for Men With Newly Diagnosed Favorable Risk Prostate Cancer | To determine the clinical impact of Gene Expression Classifier (GEC) testing in prostate cancer care while also developing a pragmatic approach for improved GEC clinical use and future study. | Multisite Crossover Assignment Interventional; 5 years | - Binomial proportion of men on active surveillance without treatment; - Occurrence of grade reclassification; - Rate of indolent pathology; - Mean score per arm of patient reported urinary function questionnaire; - Proportion of patients with changes from baseline in urinary function exceeding minimal important differences; - Mean score per arm of patient reported sexual function; - Proportion of patients with changes from baseline in sexual function exceeding minimal important differences; - Time to biochemical recurrence; - Time to distant metastases; - Mean score per arm of health-related quality of life; - Rate of adverse pathology at prostatectomy; - Rate of biochemical recurrence | Recruiting
Prolaris; NCT03290508 (https://clinicaltrials.gov/ct2/show/NCT03290508); 524 | Long-term Study to Evaluate and Clinical Outcomes in Patients with Favorable Intermediate Risk Localized Prostate Cancer | To determine whether Prolaris testing in patients with favorable intermediate risk prostate cancer influences physician management decisions toward conservative treatment in patients with Prolaris low-risk scores without negatively impacting patient oncologic outcomes, thereby sparing low-risk patients from unnecessary treatments and associated side-effects. | Prospective Observational; 8 years | - Low Prolaris score, on active surveillance; - Low Prolaris score, definitive treatment following active surveillance; - Low Prolaris score, disease progression following delayed definitive treatment; - Low Prolaris score, time to definitive treatment; - No Prolaris score, on active surveillance; - No Prolaris score, definitive treatment following active surveillance; - No Prolaris score, time to definitive treatment following active surveillance; - No Prolaris score, disease progression following delayed definitive treatment | Terminated (There are sufficient follow-up data to meet the endpoints of the study.)