# APPENDIX F PEER REVIEW DISPOSITION

Question Text | Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes
Are the objectives, scope, and methods for this review clearly described?
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes
Are the objectives, scope, and methods for this review clearly described?
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes
Is there any indication of bias in our synthesis of the evidence? | 1 | No
Is there any indication of bias in our synthesis of the evidence?
Is there any indication of bias in our synthesis of the evidence? | 2 | Yes - The bias is more so a lack of appreciation of the current flaws in risk stratification that are well documented, acknowledged even in NCCN guidelines, and the purpose of prognostic biomarkers are to improve risk stratification to enable select treatment decisions to be personalized. | We agree that there are limitations in currently used clinical risk stratification schemes and that there is a need for better evidence-based ways to accurately assess patient prognosis and personalize treatment plans.; The purpose of this review was to assess the prognostic ability of genomic classifier tests based on existing evidence. This evidence synthesis can inform clinical determinations of whether or not genomic classifier tests should be incorporated into prostate cancer management with the goal of improving prognostic assessment and treatment planning.; We have edited language in the introduction and discussion to clarify the rationale for this review and to acknowledge the limitations of existing schemas.
| 4 | No
| 5 | No
| 7 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 2 | Yes - The following randomized trials have been performed and reported with Decipher but not all included:; i. RTOG 0126; ii. RTOG 9202; iii. RTOG 9413; iv. RTOG 9902; v. RTOG 9601; vi. SAKK 09/10; vii. SPARTAN; viii. TITAN; ix. CHAARTED; x. STAMPEDE | We have reviewed the listed studies identified by the reviewer and considered them with respect to our eligibility criteria. To be included in this report, studies had to evaluate one of three a priori identified genomic classifier tests evaluated in localized prostate cancer and published in full manuscript form in a peer reviewed journal from 2010 to 4/20/2022 (see Table 1 for full eligibility criteria). Please see below for a detailed review and clarification on why these studies were not included and identification of the one that was included:; i. analysis related to Decipher reported as abstract only as ASCO GU 2/2022. No full manuscript available. Does not meet inclusion criteria; ii/iii/iv. data from these trials were analyzed together in an article that was published after search date; have identified in discussion (see “ongoing work”); v. this study was included in our review (Feng et al.2021); vi. published after our search date; identified in discussion (see “ongoing work”); vii. identified by our search but excluded for not meeting population eligibility criteria (castrate resistant prostate cancer with secondary biochemical recurrence); viii. analysis related to Decipher was presented as an abstract at ASCO 2020 and is not currently available as peer reviewed manuscript; also would not meet population eligibility criteria (metastatic prostate cancer); ix. identified by our search but excluded for not meeting population eligibility criteria (metastatic prostate cancer); x. release as preprint after our search date. Identified in the discussion (see “ongoing work”).
| 4 | No
| 5 | No
| 7 | No
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | appreciated the recommendations re areas for further research | We are glad those were found useful.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | 1. Problems with the way endpoints were used to assess benefit:; a. The panel used the following metrics to assess benefit of a biomarker:; i. Risk reclassification; 1. Reclassification to what from what? If you are saying a patient has NCCN intermediate risk disease and then has Decipher High, is this reclassification? If so this is problematic. The cutpoints used for Decipher for example have nothing to do with NCCN risk groups. In contrast, we have used prospective data to determine the reclassification from NCCN to a new integrated “clinico-genomic” model that combines NCCN and Decipher and that reclassified 67% of patients (Spratt JCO 2018). However, what is reported in this report says 21–51% and I don’t know how that was calculated. | We appreciate the concerns about risk reclassification assessment. Existing clinical risk classification systems and genomic classifier test systems use the same language for risk classification despite stemming from different data.; This key question was included to clarify to what extent genomic classifier tests offer different risk classifications from commonly used clinical risk classification systems such as NCCN. We included studies that assessed change in risk assessment with a genomic classifier test in a number of ways (including direct comparisons and integration of genomic classifier results with existing clinical risk stratification schemes such as in the example noted by the reviewer). We acknowledge that the different ways that reclassification is assessed and interpreted in the existing literature is a limitation and hinders summarization across studies. To provide clarity, we have added additional detail about our methodologic approach for this key question. In addition, we added this limitation to the discussion section.; Regarding the reported reclassification rate from Spratt et al. JCO.2018. We abstracted the data reported in Table 4 from Figure 4a and 4b in the article which is closer match to the data available from other studies in this report. We have verified the accuracy of the abstracted numbers as reported in the article. We have added reclassification findings from the second biopsy cohort that showed change from the 6-tier NCCN risk group to the 6 tier combined clinical-genomic risk group in the text (page 31) which is the cohort with 67% reclassification as mentioned by this reviewer.
| 2 | 2. Additionally, reclassification of >10% is very meaningful to patients if that changes how they would be treated. If 1 out of 10 men were classified as intermediate risk and now as low risk and don’t need treatment, that is powerful. Very few tests we order reclassify a patient the majority of the time. A bone scan in high risk disease reclassifies a patients stage ~5% of the time. | We agree that understanding what level of change in classification would be clinically meaningful is important context. Moreover, the threshold for what is clinically meaningful is not the same from one clinical context to another or even one test to another. To our knowledge, there is not an existing, well-established threshold for what is a clinically meaningful change in risk classification for patients with localized prostate cancer. This together with the fact that we found a range of reclassification rates rather than a clear estimate rate raises challenges for synthesis across studies. We have adjusted our language in the results to reflect the uncertainty in the clinical meaning of our findings.; Note that we did not explicitly consider the impact of risk reclassification on changes in treatment selection. This was not regularly reported, though a few studies reported occurrence of this secondary step after risk reclassification (see Gore 2017 and Gore 2020).
| 2 | ii. Treatment recommendation change; 1. The panel does not seem to appreciate the other biomarkers and tests done routinely change management <10% of the time, and a change of >10% is huge. Example, CT and bone scan change management ~5% of the time in men with localized prostate cancer. PSMA PET/CT changes stage of the disease 10–20% of the time. As shown in the systematic review from Jairath et al, European Urology 2021, the number needed to test for patients from the multiple Decipher studies are all <10 to change management in 1 patient. Often they are NNT of 3–4. | We appreciate that we may have mischaracterized the importance of the findings around the change in treatment management in response to test results as it relates to potential clinically meaningful threshold in terms of changes in management after testing. We note that similar to reclassification discussed above, we are unaware of an explicit agreed upon threshold for this outcome. We have adjusted our wording accordingly.
| 2 | 2. This endpoint [change in management] itself is problematic, and a major criticism of the approval of many imaging tests, as changing management doesn’t mean it is helping a patient. One must show the test is independently prognostic and that the added information enables an informed change in management. | As noted above, we agree that change in management as an endpoint has significant limitations as this reviewer mentioned and must be considered in conjunction with evidence demonstrating the tests prognostic ability. We have expanded this limitation in the discussion (see “clinical implications”, KQ2).
| 2 | iii. “Prognostic information”; 1. This is the crux of what “prognostic” biomarkers aim to do. Improve risk stratification and prognostication. We have published in Spratt et al, JCO 2018 a very large improvement of NCCN vs NCCN+Decipher (clinicogenomic model), as have others (Berlin et al, IJROBP). The improvement in AUC/C-index is quite large (10%–20%+ improvement in accuracy). That accuracy is what enables changes in management (as is now noted in NCCN guidelines under the Risk Stratification section). | We acknowledge that NCCN guidelines include mention of use of genomic classifier testing and have noted this in our appendix which highlights recommendations about these 3 genomic classifier tests in current clinical guidelines (see Appendix A).
| 2 | The sole reason we no longer give ADT to all men with intermediate risk prostate cancer getting RT is because of a moderately good prognostic model was built by me and my co-resident at the time, Dr. Zumsteg, to create what is now called favorable vs unfavorable intermediate risk (used around the world and in NCCN guidelines). All this system did was divide patients into lower and higher risk of recurrence which changed the absolute (not relative) benefit of ADT. Decipher adds to that majorly to identify ultra-low risk patients (Berlin et al, IJROBP showed no men with mostly unfavorable intermediate risk who got RT alone developed mets with Decipher low; RTOG 0126 we showed that Decipher low patients had only a 4% risk of mets at 10 years with RT alone, but a 16% risk of mets for Decipher high patients). | To date analysis of RTOG 0126 with respect to Decipher has only been published in abstract form. As noted above, our eligibility criteria required full peer-reviewed publications for eligibility. We added a note to the discussion (see “ongoing work”) that more evidence is likely forthcoming in the literature.; The study by Berlin noted by the reviewer was included in this review and is considered within the context of the breadth of literature identified.; Of note, Berlin et al indicate the need for a prospective clinical trial which is currently underway (GU010); this trial is listed in appendix 5.
| 2 | 2. Data used; a. The following randomized trials have been performed and reported with Decipher but not all included:; i. RTOG 0126; ii. RTOG 9202; iii. RTOG 9413; iv. RTOG 9902; v. RTOG 9601; vi. SAKK 09/10; vii. SPARTAN; viii. TITAN; ix. CHAARTED; x. STAMPEDE | Thank you for bringing these to our attention. Please see our above response regarding these trials individually.
| 2 | 3. Assessment of quality; a. This review/summary paper will be criticized majorly given the Simon criteria, the most widely used criteria to assess the quality of prognostic biomarkers, would state Decipher is level 1–2 and Prolaris and Oncotype are 3. However, the panel states the evidence for Decipher is low and Prolaris and Oncotype are very low. How is having >40 studies, >10 completed RCTs profiled, show “low” evidence for Decipher? NCCN guidelines classifies it as level 1 evidence now. | The certainty of evidence statement reflects a determination of the totality of the existing evidence with consideration of how it applies to the specific question at hand. This incorporates but is not equivalent to the quality (or risk of bias) assessment of each individual study. The certainty of evidence determination is driven by GRADE criteria which is the current standard for systematic reviews. For this review, we frequently downgraded our assessments due to the fact that most all identified studies were older and included patients that received during a distinctly different practice era from current modern management options. In addition, our assessments were downgraded for considerations such as inconsistency of effects (i.e. variation across included studies) and imprecision (i.e. wide confidence intervals in setting of relatively few events). Thus, it is possible to have a large number of relevant studies but still have low certainty of evidence as it relates to the specific question driving the review.
| 4 | Some comments:; 1) what percent risk reclassification would the panel consider to be significant to recommend genomic testing using any of the validated panels? Key finding bullet 2 suggests that a significant minority of men DO have risk reclassification, and while not the majority, this could still be important for up to 40% of men! There is a general lack of any thought or opinion here on what rate of reclassification is significant and would be of interest to the panel, particularly if the genomic classification has more prognostic value than the clinical NCCN classification. Suggest revisions to KQ1. | As noted above, we agree that the determination of what is a clinically significant determination of risk reclassification is driven by clinical practice standards rather than the existing data. We appreciate that we did not frame this part of the discussion accurately and have reworded the implications of this percentage accordingly as noted above.
| 4 | 2) The evidence for the DECIPHER to provide more than just a prognostic effect in the salvage RT setting seems stronger than other settings and for other biomarkers/genomic classifiers, based on the phase 3 RTOG 9601 trial (Feng F et al JAMA Oncol 2021). For example, men with low PSA values <0.7 in the early salvage post RP setting and with a low risk DECIPHER profile had no benefits and potential harms from hormonal therapy with salvage RT, while those with a high risk DECIPHER profile had a survival benefit. This really deserves more attention and recommendation in my opinion given the phase 3 controlled setting with long term follow up and potential clinical utility to VA patients and cost savings/QOL impact on veterans who may be able to avoid 2 years of hormonal therapy and the low harms of performing this classifier on RP tissue. Data is not strong here for other classifiers in the salvage RT setting. Suggest revisions to KQ2 post RP especially around p45 and 56. Adjuvant RT is seldom offered anymore, but early salvage RT is. This randomized trial and study is not even discussed in KQ2. Suggest this remains relevant to men with localized PC and management decision making post-RP for those with PSA recurrence. If the authors wish to avoid this setting, this needs to be clearly discussed still as outside of the scope of the questions around initial management, but I think the panel should take this on. Limiting itself to just discussions around reclassification and prognostic importance misses this important aspect of clinical utility where in my opinion is the ONLY setting where a genomic classifier has demonstrated clinical utility. | We appreciate the reviewer’s interest in evidence about response to treatment among patients with different classifier identified risk levels.; However, this was not within the scope of this review as designed with those who nominated this work.; KQ2 asks if treatment decisions were changed based on the results of receipt of test results and is not structured to evaluate if patient outcomes vary by treatment received depending on genomic classifier test risk stratification. We have added explicit notation of this in the discussion (see 2^nd^ paragraph of Limitations). This issue may be an appropriate focus for a future review.
| 4 | 3) Perhaps a statement about pathology AI biomarkers being outside of the scope of this report on genomic classifiers? This could be the subject of a separate review given emerging evidence on the clinical utility of the Artera AI pathology biomarker across several contexts for prognosis and prediction of hormonal therapy benefit in a radiation oncology context (intermediate risk PC). | AI based biomarkers, whether based on pathology, radiomics, or other datasets, are outside the scope of this current review but could be considered in the future when sufficient primary data is available. We have noted this as suggested in our discussion section (see “limitations”)
| 4 | 4) The panel could speculate on what the potential harms are for performing a genomic classifier. The test does not require a new biopsy or ANY direct harms and does not disclose ANY genetic or familial risk or PHI disclosure. The only harms are really the costs. The costs should be discussed therefore within the VA, as compared to the benefits and cost savings, for example of avoiding unnecessary treatment like 2 years of ADT. | We agree that this is an important consideration for contextualizing the findings in this review. We have added a statement about the issue of harms from this test as suggested in our discussion (see first paragraph).
| 5 | The prostate Oncotype scare is no longer owned by Exact Sciences and is now owned by MDX and renamed Prostate GPS as they were not allowed to use the name Oncotype when they purchased it. | Thank you for this clarification.
| 7 | This is an excellent analysis that is very appropriate for the “moment”. It does an outstanding job of addressing the key questions in a way that is comprehensive, unbiased, relevant and useful. It far exceeded my expectations. | Thank you.