# APPENDIX E STUDY CHARACTERISTICS

Study; Study Acronym; Country; KQ; Design; Total Enrolled | Cohort Years; VA Patients | Patient Enrollment Criteria | Patient Demographics; Age; Race; PSA; Gleason; T Stage | Test Type; Tissue Used; Clinical Risk Tool | Outcomes Reported; Risk of Bias | Funding and Conflicts
Badani, 2015b^24^; Northeast, USA; KQ1; KQ2; Prospective before and after test (own patients); 175 | Approximately 2013; No VA patients | Men with very low, low, and intermediate risk who were being considered for active surveillance had Oncotype test run prospectively, questionnaires complete pre and post result | Mean age: 63.9 (7.26); Race:; 76.6% White; 12.0% Black; 5.7% Hispanic; 1.3% Asian; PSA:NR; Gleason: 70.3% Group 1; 29.7% Group 2; T stage:; 89.2% T1c; 10.1% T2a; 0.6% T2b | Median Oncotype score: NR; Biopsy; NCCN; 22.2% Very low risk; 44.9% Low risk; 32.9% Favorable; Intermediate | Difference in classification; Proportion choosing active surveillance; Overall: KQ1 Low ROB; KQ2 Serious | Genomic Health
Badani, 2015a^29^; ASSESS-D; US; KQ2; Deidentified case history review with and without test; 110 cases; 51 Urologists | NR; No VA patients | Consecutive patients presenting with pT3 disease or positive surgical margins after surgery; unavailable prostate tissue or failure to achieve PSA nadir after RP were excluded; urologists were US board-certified recruited from AUA membership directory and high-volume surgeons referred by co-authors | Mean age: NR; Race: NR; PSA: NR; Gleason: NR; T stage: NR | Median Decipher score: NR; Prostatectomy; Clinical risk classification: NR | Change in management/treatment decision-making; Overall: Low ROB | GenomeDx biosciences, national research council of CANADA Industrial Research Assistance Program
Badani, 2013^30^; DECIDE; United States; KQ2; Deidentified case history review with and without test; 24 | NR; cases from prior GC validation study in high-risk post-RP men; No VA patients | Patients post radical prostatectomy who either had adverse pathology or evidence of biochemical recurrence through PSA | Age range: 57–74; Race: NR; PSA: <10: 79%%; 10–20: 12.5%; >20: 4.1%; NA: 4.1%; Gleason:; 6: 25%; (3+4): 25%; (4+3): 21%; 8: 25%; 9: 12.5%%; 10: 4.1%; T stage:; pT2 58.3%; pT3 42% | Mean Decipher score: NR; Prostatectomy; D’Amico risk groups:; Low: 12.5%; Intermediate:46%; High: 42% | Change in management/treatment decision-making; Overall: Critical ROB | Company (GenomeDx Biosciences)
Berlin, 2019^49^; Toronto, Canada; KQ3; Retrospective observational | 2005 and 2011; No VA patients | Men diagnosed with NCCN-defined IR prostate cancer treated with curative-intent DE-IGRT without neoadjuvant, concomitant, or adjuvant ADT | Median age: 72.4; (Range: 68.4–75.0); Race: NR; PSA: 7.8; (Range: 5.7–11.2); Gleason:; 1 (3+3) 9.9%; 2 (3+4) 62.0%; 3 (4+3) 28.1%; T stage:; cT1c/T2a 78.5%; cT2b/T2c 21.5% | Decipher score:; Low 72.7%; Intermediate 14.9%; High 12.4%; Biopsy; NCCN:; Favorable 27.3%; Unfavorable 71.9%; Unknown 0.8% | Biochemical recurrence-free survival; Metastasis-free survival; Overall: High ROB | The Terry Fox Research Institute (TFRI),
Bishoff, 2014^71^; USA and Germany; KQ3; Retrospective observational; Linked paper: Tosoian 2017^56^ | Martini-Clinic: 2005–2006, Durham VA 1994–2005, Intermountain HealthCare 1997–2004; VA patients | Patients with localized prostate cancer who underwent radical p rostatectomy | Median age: 62; Race: NR; PSA median: 6.4 Gleason; Less than 7: 58%; 7: 35%; Greater than 7: 7%; T stage; T1: 61%; T2: 32%; T3: 1% | Prolaris: 0 (IQR range – 0.9 to 0.9); Biopsy; Clinical risk classification: NA | Biochemical recurrence-free survival; Overall: High ROB | Undisclosed
Brooks, 2021^39^; Cleveland, USA; KQ3; Retrospective observational | Between 1987 and 2004; No VA patients | All patients who underwent RP | Mean age: 61 (SD 6); Race:; White 82%; Black 13%; Asia/Hispanic: 5%; PSA; ≥4: 14%; >4–10: 68%; >10–20: 13%; >20: 5%; Gleason; 3: 62%; 3+4: 8%; 3+5: 1%; 4: 23%; 4+3: 3%; 4+5: 2%; 5, 5+4: 1%; T stage; T1A: <1%; T1B: <1%; T1C: 65%; T2A: 24%; T2B: 7%; T2C: 3% | Median Oncotype: 26 (19 to 39); Prostatectomy; AUA:; Low/very low 55%; Intermediate 35%; High 10% | Metastasis-free survival; Prostate-specific mortality; Overall: Low ROB | N/A
Canfield, 2017^31^; NR; US; KQ2; Retrospective, comparative cohort before-after testing availability | 2013–2016; No VA patients | Patients age >18, AUA low risk, clinical activity for at least 12 months before and 6 months after diagnosis, at least 1 PSA within 12 months before or after dx | Age %; ≤50: 2%; 50–59: 21%; 60–64: 20%; 65–69: 22%; 70–79: 27%; ≥80: 7%; Race: NR; PSA; ≤10: 100%; Gleason; 6: 100%; T stage; T1-T2a: 100% | Oncotype score: NR; Biopsy; AUA:; Low risk 100% | Proportion choosing active surveillance; Overall: Moderate ROB | Genomic Health Inc (Redwood City, CA)
Canter, 2020^46^; USA, New Orleans, LA; Durham, NC; Salt Lake City, UT; Hamburg, Germany; KQ3; Retrospective observational | Martini Clinic- 2005–2006; Durham VA- 1994–2005; Intermountain- 1997–2004; Ochsner Clinic- 2006–2011; Some VA patients | Patients with localized prostate carcinoma treated with radical prostatectomy or radiotherapy (external beam radiation +/− androgen deprivation therapy or brachytherapy) with available clinicopathological and molecular data | Median age: 63 (IQR 58 to 70); Race:; Black: 29%; Non Black: 71%; PSA median; 5.9 (IQR 4.5, 9.0); Gleason; <7: 46%; (3+4): 23%; (4+3): 8.4%; >7: 12%; T stage; T1: 69%; T2: 29%; T3: 2.4% | Prolaris score median: 0.1 (IQR −0.6, 0.9); Prostatectomy; CAPRA:; Low: 46%; Intermediate: 42%; High: 12% | Metastasis-free survival; Overall: Low ROB
Canter, 2019^48^; NA; New Orleans, LA, USA; KQ3; Retrospective observational | 2006–2011; No VA patients | Patients with clinically localized prostate carcinoma with available b iopsy sample | Median age: 64.5 (IQR range 58, 70); Race:; Black 36.6%; Non-Black: 63%; PSA median: 6.35; Gleason; <7: 51%; (3+4): 24%; (4+3): 10%; >7: 15%; T stage; T1: 73%; T2: 23%; T3: 4% | Prolaris median score: 0.3 (−0.2, 1.0); Biopsy; CAPRA median: 3 (2–5) | Metastasis-free survival; Prostate-specific Mortality; Overall: Low ROB | Myriad Genetic Laboratories, Inc
Cooperberg, 2015^66^; NA; Rochester, MN; USA; KQ3; Retrospective observational | 2000–2006; No VA patients | High risk (PSA >20, Gleason >=8, stage pT3b) prostate carcinoma selected randomly (20% including 11 cases; case cohort) from a population of 1010 patients enrolled prospectively | Median age: 63.5; Race: NA; PSA; <10: 56%; 10–20: 28%; >20: 17%; Gleason; ≤6: 8.1%; 7: 49%; ≥8: 43%; T stage: NR | Decipher score; <0.4: 54%; 0.4–0.6: 22%; >0.6: 24%; Prostatectomy; CAPRA score; <3: 0.5%; 3–5: 55%; >5: 44% | Prostate-specific mortality; Overall: Low ROB | Mayo Prostate Cancer SPORE grant; Richard M. Schulze Family Foundation; National Research Council of Canada Industrial Research Assistance Program, Mayo Foundation For Medical Education and Research and GenomeDx Biosciences Inc.
Cooperberg, 2013^68^; NA; San Francisco, CA; KQ3; Retrospective observational | 1994–2011; No VA patients | Patients with prostate carcinoma who underwent RP without adjuvant or neoadjuvant therapy with >5 years follow-up | Median age: 63; Race: NR; PSA; ≤6: 48%; >6 to 10: 30%; >10 to 20: 16%; >20: 6%; Gleason; 2 to 6: 52%; 7: 42%; 8 to 10: 5%; T stage: NR | Prolaris score:; ≴−1: 7%; >−1 to 0: 50%; > 0 to 1: 34%; >1: 9%; Prostatectomy; CAPRA-S; Low (0 to 2): 63%; Intermediate (3 to 5): 28%; High (6 to 12): 8% | Biochemical recurrence-free survival; Overall: Low ROB | Peter R. Carroll, Myriad
Crawford, 2014^34^; NA; US; KQ2; Prospective pre/post-test result; 331 | July 19 to December 9, 2013; No VA patients | CCP ordered on patient with documented prostate c ancer | Mean age: 67.4 (SD 7.43); Race: NR; PSA mean: 7.7 (8.07); Gleason; ≤6: 51.7%; (3+4): 28.7%; (4+3): 12.1%; 8–10: 7.5%; T stage; T1a: 1.5%; T1b: 0.3%; T1c: 82.5%; T2a: 7.3%; T2b: 4.2%; T2c: 3.9%; T3b: 0.3% | Mean Prolaris score: −0.69 (SD 0.82); Biopsy; AUA; Low: 43.5%; Intermediate: 44.1%; High: 12.4% | Change in management/treatment decision-making; Overall: Serious ROB | Myriad Genetics
Cullen, 2015^65^; CPDR (center for prostate cancer research) longitudinal study; US; KQ3; Retrospective observational | 1990 to 2011; No VA patients | Post RP with NCCN very low, low, intermediate risk | Mean age: 61.0 (SD 7.5); Race:; White: 75.9%; Black: 20.4%; Other: 3.7%; PSA; <4: 22.9%; 4–9.99: 67.9%; 10–20: 9.2%; Gleason; 3+3: 73.4%; 3+4: 23.4%; 4+3: 3.2%; T stage; T1: 68.7%; T2: 31.3% | Median Oncotype NR; Biopsy; NCCN; Very low: 11.0%; Low: 53.6%; Intermediate: 35.5% | Biochemical recurrence-free survival; Overall: Low ROB | Center for prostate cancer research; uniformed services university of the health sciences; Genomic Health Inc.
Cuzick, 2012^69^; England; KQ3; Retrospective observational; Linked paper: Cuzick, 2011 ^4^ | 1990 and 1996; No VA patients | Men who had conservatively treated clinically localized prostate cancer, which was diagnosed by use of needle biopsy, were younger than 76 years at the time of diagnosis and had a baseline PSA measurement.; Patients treated with or radiation therapy, within the first 6 months after diagnosis, or were excluded | Age: NR; Race: NR; PSA: NR; Gleason; <7: 30%; 7: 43%; >7: 26%; T stage; T1: 11%; T2: 30%; T3: 46% | Median Prolaris score: 1.03 (IQR range 0.41 to 1.74); Prostatectomy; Clinical risk classification: NR | Prostate-specific mortality; Overall: Moderate ROB | Queen Mary University of London
Cuzick, 2015^62^; NA; UK; KQ3; Retrospective observational | 1990–2003; No VA p atients | Age <76 years at diagnosis and had clinically localized prostate cancer diagnosed b y needle biopsy | Age; 70.8 (IQR 66.5 to 73.6); Race: NR; PSA; ≤4: 2.6%; >4–10: 30%; >10–25: 35%; >25–50: 18%; >50–100: 14%; Gleason; 3+3: 26%; 3+4: 34%; 4+3: 22%; >7: 19%; T stage; NR | Median Prolaris: 0.40 (IQR −0.10 to 1.00); Biopsy; CAPRA; 0–2: 14%; 3–5: 35%; 6–7: 23%; 8–10: 28% | Prostate-specific mortality; Overall: Low ROB | Cancer Research UK, ORCHID, National Institutes of Health (SPORE), the Koch Foundation and Myriad Genetics. This work was supported by Cancer Research UK, Queen Mary University of London, Orchid Appeal, US National Institutes of Health, and Koch Foundation.
Cuzick, 2011^4^; Temple, Texas, USA, and UK; KQ3; Linked paper: Cuzick, 2012^69^ | 1985–1995 for US cohort, 1990–1996 for UK cohort; No VA patients | For us cohort: All patients undergoing radical prostatectomy for prostate cancer.; For UK cohort: Men who had clinically localized prostate cancer diagnosed by transurethral resection of the prostate (TURP), were under age 76 years at the time of diagnosis and had a baseline PSA measurement | Median Age: 68 (IQR 62, 72); Race; Non-White: 7.3%; PSA: 6.9 (4.3, 12.4); Gleason; <7: 67.6%; 7: 22.8%; >7: 9.6%; T stage:; T1: 33%; T2: 67%; T3: <1% | Median Prolaris score: 0.16 (IQR −3.30, 0.64); Biopsy Prostatectomy; Clinical risk classification: NR | Biochemical recurrence-free survival; Prostate-specific mortality; Overall: Low ROB | Queen Mary University of London, NIH; SPORE, Koch Foundation
Dalela, 2017^57^; Various US academic sites and VA; KQ3; Retrospective observational | 1990–2010; Some VA patients | Patient who had radical prostatectomy with adverse features had Decipher test run to see if adding it to standard adverse clinical features could improve prediction of those that would benefit from adjuvant radiation therapy | Median Age: 61 (IQR 57, 65); Race: NR; Median PSA: 8.1 (IQR 5.5 to 12.7); Gleason; 3+3: 8.0%; 3+4: 43.2%; 4+3: 21.9%; 8: 11.1%; 9–10: 15.4%; T stage; T2: 27.7%; T3a: 39.3%; T3b: 28.3%; T4: 4.7% | Median Decipher score: 0.41 (IQR 0.26, 0.56); Prostatectomy; Clinical risk classification: NR | Time to Clinical Recurrence; Overall: Moderate ROB | Unclear (mainly GenomeDx Biosciences)
Dall’Era, 2015^32^; NA; US; KQ2; Retrospective cohort (comparative); 211 | 2012–2013 (pre); 2013–2014 (post); No VA patients | Physicians who ordered at least 4 Oncotype Dx tests between May 2013 and Feb 2014 were asked to participate. Those providers then selected at least 7 patients diagnosed with prostate cancer between May 2012 and April 2013, with low or low-intermediate risk prostate cancer, baseline PSA <20, clinical stage T1c-T2c, and no other genomic testing for prostate cancer as the pre cohort. study physicians given eligible cases for GPS (post) cohort | Median age: 64.9 (10.1); Race; Black: 16%; White: 78%; Other: 6%; PSA; 0 – 4: 27%; >4 – <10: 70%; 10 – 20: 2%; >20: <1%; Gleason; 3+3 or less: 85%; 3+4 15%; T stage; T1a/b: 2%; T1c: 92%; T2a: 4%; T2b: 1% | Baseline median Oncotype score: 7 (range 4 to 13); GPS group median Oncotype score: 7 (range 1 to 7); Biopsy; NCCN:; Very low or low: 82% | Proportion choosing active surveillance; Overall: Serious ROB | Unknown
Den, 2015^63^; Philadelphia and Rochester MN, USA; KQ3; Retrospective observational; 186 | 1990 and 2009; No VA patients | All patients with pT3 disease and/or positive surgical margins who received post-RP RT | Median age: 61 (IQR 56 to 66); Race: NR; Median PSA: 7.8 (IQR 5.3 to 12.3); Gleason; ≤6: 14.9%; 3+4: 31.9%; 7 (4+3): 26.6%; ≥8: 25.5%; Unknown: 1.1%; T stage: NR | Decipher score; Low: 39%; average: 41%; High: 20%; Prostatectomy; CAPRA-S; Low: 5%; Intermediate: 50%; Hight: 45% | Metastasis-free survival; Overall: Low ROB | GenomeDx Biosciences
Erho, 2013^6^; NA; Rochester, MN, USA; KQ3; Retrospective case control | 1987–2001; No VA patients | Patients with prostate carcinoma post radical prostatectomy and classified into no evidence of disease group, PSA recurrence group and clinical metastasis group | Age: 66 (IQR 61 to 70); Race: NR; PSA:; <10: 92; 10–20: 33; >20: 50; NA: 11; Gleason; ≤6: 9.7%; 7: 52%; 8: 12%; 9: 25%; 10: 0.5%; T stage; pT2N0M0: 40%; pT3/4N0M0: 46%; pTanyN+M0: 15% | Median Decipher score: NR; Prostatectomy; Clinical risk tool: NR | Metastasis-free survival; Overall Survival; Prostate-specific Mortality; Overall: Low ROB | National Research Council of Canada, Industrial Research Assistance Program and the Mayo Clinic Prostate Cancer SPORE
Eure, 2017^20^; US; KQ1; Comparative cohort before (retrospective) and after (prospective) institutional testing; 258 | 2014–2015; No VA patients | Patients with low risk prostate cancer recommended to be on active surveillance asked to participate prospectively by getting Oncotype testing and then shared decision making whether to stay on AS | Age; <65: 55%; ≥65: 45%; Race:; White 81%; Black: 15%; Asian: 0.8%; Other: 3.4%; PSA; 0–4: 19%; 4.1–9.9: 72%; 10–20: 8.7%; Gleason; 3+3: 75%; 3+4: 25%; T stage; T1c: 87%; T2a: 11%; T2b: 2%; T2c: 0.9% | Median Oncotype: NR; Biopsy; NCCN; Very low: 29%; Low: 40%; Intermediate: 31% | Proportion choosing active surveillance; Change classification reclassification; Overall: Moderate ROB | Unclear
Feng, 2021^41^; NA; US and Canada (NRG Oncology Radiation Therapy Oncology Group member sites); KQ3; Prospective observational; 760 | 1998–2003 (study conduct); No VA patients | History of RP with lymphadenectomy at pathologic tumor stage T2 or T3 without nodal involvement, and detectable PSA at least 8 weeks after surgery of 0.2 to 4; karnofsky performance score of 80+, no prior chemo/radiation therapy/hormone therapy other than short period hormonal treatment; no evidence metastasis, no liver disease and had a life expectancy of 10+ years | Median age: 64.5 (IQR 60–70); Race; White: 89.2%; Hispanic: 1.7%; Black: 7.1%; Asian: 1.1%; American Indian: 0.3%; Other 0.6%; Median PSA at trial entry: 0.7 (IQR 0.4, 1.1); Gleason; 2–6: 29.5%; 7: 53.7%; 8–10: 16.5%; Unavailable: 0.3%; T stage; T2: 33.5%; T3: 66.5% | Median Decipher score: 0.435 (0.28, 0.58); Prostatectomy; Clinical risk tool: NR | Metastasis-free survival; Overall Survival; Prostate-specific mortality; Overall: Low ROB | This study was supported by grant from NRG Oncology Operations, grant from NRG Oncology SDMC, grant from NCORP, grant from NRG Specimen Bank, and grant R01 from the National Cancer Institute and Decipher Biosciences.
Freedland, 2013^67^; Durham, NC; KQ3; Retrospective observational | 1991–2006; VA patients | Men who had XRT for prostate cancer and CCP score of their biopsy and regression analysis done to see if CCP score added value above usual clinical parameters of high recurrence risk | Median age: 66 (IQR 60, 71); Race; Black: 57.4%; Other: 42.6%; Median PSA: 0.04 (IQR 5.25, 13.47); Gleason; <7: 38.3%; 7: 49.6%; >7: 12.1%; T stage; T1: 60%; T2: 36.7%; T3: 3.3% | Median Prolaris score: 0.12 (−0.43, 0.66); Biopsy; D’Amico; Low: 27.3%; Intermediate: 51.8%; High: 20.9% | Biochemical recurrence-free survival; Overall: Moderate ROB | Myriad
Gaffney, 2019^17^; Northeast US; KQ1; Retrospective observational | 2015–2018; No VA patients | Patients who had GPS sent out during the 3-year p eriod | Mean age: 65.2 (SD 7.3); Race: NR; Mean PSA: 6.5 (3.2); Gleason:; 3+3: 65%; 3+7: 35%; T stage: NR | Oncotype; Very low: 34.3%; Low: 28.4%; Intermediate: 36.7%; High: 0.8%; Biopsy; NCCN; Very Low: 23.1%; Low: 33.6%; Intermediate 43.3%; High: 0% | Change in management/treatment decision-making; Change classification reclassification; Overall: Moderate ROB | Institutional
Glass, 2016^60^; Northwest US; KQ3; Retrospective observational; Linked paper: Spratt, 2017^95^ | 1997–2009; No VA patients | Decipher test was performed for men undergoing prostatectomy who had high risk features preoperatively (PSA > 20 or GS 8 or higher) or post prostatectomy high risk features pT3 or +SM | Median age: 57 (46, 67); Race; White 93.8%; Black: 2.2%; Other: 4%; Median PSA: 6.1 (IQR 4.8, 8.9); Gleason (at RP):; ≤6: 39.3%; 7: 38.8%; 8: 15.6%; ≥9: 5.4%; Unknown: 0.9%; T stage: NR | Median Decipher: 0.32; Prostatectomy; CAPRA-S; Low: 20.5%; Intermediate: 60.7%; High: 18.8% | Biochemical recurrence-free survival; Clinical Recurrence; Overall: Low ROB | Institutional
Gore, 2020^27^; USA; KQ2; Prospective before-after test (own patients); 246; Linked paper: Gore, 2017^36^ | May 2014 to February 2016; No VA patients | Post radical prostatectomy patients being considered for immediate adjuvant radiation therapy (ART) or early salvage radiation therapy (SRT). ART patients had T3 disease. SRT patients had biochemical recurrence after initial nadir post RP (PSA > or equal to 0.2 ng/mL on 2 assessments) | Median age: 63.0 (IQR 48, 74.9); Race; White: 89%; Other: 11%; Unknown: 0.4%; PSA at diagnosis: NR; ≥10: 25%; Unknown: 2%; Gleason; Group 1: 4.5%; Group 2: 47%; Group 3: 29%; Group 4: 9.8%; Group 5: 9.8%; T score; pT2: 36%; pT3a: 42%; pT3b: 13%; Unknown: 7.7% | Decipher; Low: 39%; Intermediate: 24%; High: 36%; Prostatectomy; Clinical risk tool: NR | Addition of ADT to definitive radiation; Proportion choosing active surveillance; Receipt of adjuvant radiation with or without ADT; Overall: Moderate ROB | Decipher Biosciences Inc, San Diego, CA
Howard, 2020 ^44^; Durham VA; KQ3; Retrospective observational | 1989–2016; VA patients | VA men who underwent RRP at high risk for recurrence - assessed predictive ability of Decipher compared to CAPRA for metastasis and recurrence, also analyzed by Black race | Median age: 62 (57, 65); Race; Black: 55%; White: 43%; Other: 2%; Unavailable: <1%; Median PSA: 7.1 (IQR 5.1, 10.8); Gleason; 1: 12%; 2: 61%; 3: 15%; 4: 5%; 5: 7%; T stage; pT2: 56%; pT3a: 18%; pT3b: 18%; pT4: 8% | Decipher; Low: 51%; Intermediate 24%; High: 25%; Prostatectomy; CAPRA-S; Low: 10%; Intermediate: 62%; High: 28% | Metastasis-free survival; Prostate-specific mortality; Overall: Low ROB | Decipher; Biosciences
Karnes, 2018 ^54^; US multi group study; KQ3; Retrospective observational | 1987–2010; Some VA patients | Patients who had prostatectomy with adverse pathology retrospectively had Decipher testing to correlate with prostate-cancer-specific mortality | Median age: 62 (IQR 58, 67); Race: NR; PSA; <10: 55%; 10–20: 28%; >20: 17%; Gleason; ≤6: 7%; 7: 57%; 8–10: 37%; T stage: NR | Decipher; 0.39 (IQR 0.23, 0.59); Prostatectomy; CAPRA-S; <3: 19%; 3–5: 42%; >5: 39% | Prostate-specific mortality; Overall: Moderate ROB | DOD/PCRP, Prostate Biorepository Network, Hopkins SPORE, GenomeDx
Klein, 2016 ^22^; Cleveland/ USA; KQ1; KQ3; Retrospective observational; Linked paper: Klein, 2015^64^ | Between 1987 and 2008; No VA patients | Preoperative prostate-specific antigen (PSA) >20 ng/mL or stage pT3 or margin positive or pathologic Gleason score ≥8 | Median age: 62 (IQR 58, 67); Race; White: 77.2%; Black: 19.3%; Asian: 3.5%; Median PSA: 6.3 (IQR 5.1, 11.1); Gleason; ≤6: 24.4%; 7: 24.6%; ≥8: 7.0%; Unknown: 7.0%; T stage; T1c: 63.1%; T2a: 31.6%; T2b: 5.3% | Median Decipher 0.38 (IQR 0.29–0.49); Biopsy Prostatectomy; NCCN; Low: 40.4%; Intermediate: 47.4%; High: 7.0%; Unknown: 5.3% | Change classification reclassification; Metastasis-free survival; Overall: KQ3 Moderate ROB KQ1 Low ROB | Many of authors are employees of GenomeDx Biosciences. Two of the authors received an unrestricted research grant from GenomeDx Biosciences (GENDX1208) to support the costs of this study.
Klein, 2015^64^; Cleveland, USA; KQ3; Linked paper: Klein, 2016 ^22^ | 1987 and 2008; No VA patients | Preoperative prostate-specific antigen (PSA) >20 ng/ml, stage pT3 or margin positive, and no clinical or radiographic evidence of metastasis or pathologic Gleason score 8; pathologic node-negative disease; undetectable post-RP PSA; no neoadjuvant or adjuvant therapy; and a minimum of 5-yr follow-up for those who remained metastasis free. | Median age: 62 (range 42, 74); Race; White: 89.9%; Black: 8.3%; Asian: 2%; Other: 0.6%; Median PSA: 6.54 (range 0.1, 66.6); Gleason; ≤6: 13.6; 7: 62.1; 8: 11.8; 9: 12.4; T stage: NA | Median Decipher 0.35 (range 0.03, 0.91); Prostatectomy; Median CAPRA-S: NR | Metastasis-free survival; Overall: Low ROB | GenomeDx Biosciences Inc.
Kornberg, 2019^47^; San Francisco, CA, USA; KQ3; Retrospective observational | 2001–2016; No VA patients | Prostate carcinoma patients on active surveillance who had radical prostatectomy at least 6 months after starting on AS. Participants were diagnosed with Gleason 3 + 3 or low volume 3 + 4 cancer, organ-confined disease, PSA less than 20 ng/ml and a clinical CAPRA risk of 0 to 5. | Mean age: 60.7 (SD 6.8); Race; Asian: 2%; Black: 2%; White: 89%; Other: 6%; Median PSA: 5.3 (4.2, 7.0); Gleason:; 3+3: 72%; 3+4: 28%; T stage; T1c: 67%; T2: 3%; T2a: 24%; T2b: 3%; T2c: 3% | Median Prolaris 26.4 (18.8, 34.6); Biopsy; CAPRA; Low: 83%; Intermediate: 17% | Biochemical recurrence-free survival; Overall: Moderate ROB | Goldberg-Benioff Program in Translational Cancer Research, Genomic Health, Inc. institutional support and United States Department of Defense Prostate Cancer Research Program Grant W81XWH-13-2-0074
Leapman, 2018 ^50^; Na; San Francisco, CA, USA; KQ3; Retrospective observational | Until August 1, 2017; No VA patients | Patients with clinically localized prostate carcinoma who were treated with radical p rostatectomy | Median age: 59 (54, 64); Race; Native American:<1%; Asian/Pacific Islander: 3%; Black: 4%; White: 84%; Mixed: 6%; Unknown: 3%; Median PSA: 5.9 (IQR 4.6, 8.1); Gleason; 1: 64%; 2: 23%; 3: 6%; 4–5: 7%; Missing n=17; T stage; T1c: 38%; T2: 61%; T3: 1%; Missing n=17 | Median Prolaris −0.33 (IQR −0.69, 0.18); Biopsy; CAPRA-S; Low: 66%; Intermediate: 27%; High: 28% | Biochemical recurrence-free survival; Metastasis or PCSM; Overall: Low ROB | Zero Cancer Foundation, Jim Lafferty Memorial Research Grant.
Lehto, 2021^40^; NA; Finland; KQ3 | 1992–2015; No VA patients | Men treated with RP with pathology showing Gleason score 4 (GS 3+3, 4+3, 4+4) and histopathologic tumor\ stage 2–3; had to have complete clinical data available; no neoadjuvant treatment | Median age- cases: 63 (IQR 9.7); Median age- controls: 62 (IQR 8.0); Race: NR; Median PSA- cases: 9.5 (IQR 6.0); Median PSA- controls: 9.0 (IQR 7.0); Gleason; 3+4: 39%; 4+3: 41%; 8: 20%; T stage; T2 35%; T3a: 34%; T3b: 31 % | Decipher; Prolaris; Oncotype (Medians NR); Prostatectomy; Clinical risk tool: NA | Metastasis-free survival; Prostate-specific mortality; Overall: High ROB | Cancer Foundation Finland; Academy of Finland, Hospital Disctrict of Helsinki and Uusimaa, Grant/Award Sigrid Jusélius Foundation
Leon, 2018^51^; NA; France; KQ3; Retrospective observational | 2000–2007; No VA patients | Patients post RP for prostate cancer | Median age: 63 (IQR 58, 67); Race: NR; Median PSA: 8.0 (IQR 5.8, 11.0); Gleason; <7: 36%; 3+4: 30%; 4+3: 27%; >7: 7%; T stage: NR | Median Prolaris score: 0.08 (IQR −0.36, 0.57); Prostatectomy; Median CAPRA-S: 3 (IQR 1, 4) | Biochemical recurrence-free survival; Overall: High ROB | Myriad Genetics
Lynch, 2018^18^; 6 US VAMCs; KQ1; KQ2; cohort before/after test availability; 390 | Retrospective: January 2014 and March 2015.; Prospective: March 2015 and February 2016; VA patients | Newly diagnosed NCCN very low, low, intermediate risk prostate cancer; intermediate had Gleason 3+3, PSA 10–20 or bx Gleason 3+4 with 3 or fewer pos biopsy cores and 33% or less positive cores for tumor and PSA less than 20; for prospective cohort - had not yet made a management decision | Median age: 66 (range 43, 83) (untested) 66 (range 50–85) (tested); Race:; White: 75%; Black: 17%; Other: 6.9%; PSA: NR; Gleason; 3+3: 69%; 3+4: 31%; T stage: NR | Median Oncotype 26.5 (range 0, 61); Biopsy; NCCN; Very low: 20%; Low: 40%; Intermediate: 40% | Change in management/treatment decision-making; Proportion choosing active surveillance; Change classification reclassification; Overall: KQ1 Low ROB; KQ2 Moderate ROB | Genomic Health Inc, the company that has exclusive rights to conduct the 17-gene Genomic Prostate Score assay. Funding was provided to the Veteran Healthcare Administration, not to individual authors
Michalopoulos 2014^26^; US; KQ1; KQ2; Prospective before-after test (own patients); 146 | 2013; No VA patients | Patients who underwent radical prostatectomy in a community-based practice and who presented adverse pathological findings | Median age: 63 (IQR 59, 67); Race: NR; PSA; <10: 79.5%; 10–20: 12.3%; >20: 8.2%; Gleason; 6: 13.7%; 3+4: 37%; 4+3: 29.4%; 8: 8.9%; 9: 9.6%; 10: 0.7%; Unknown: 0.7% | Median Decipher probability of metastasis: 4.2% (IQR 2.8, 9.6%); Prostatectomy; CAPRA-S; Low: 16.4%; Intermediate: 55.5%; High: 21.9%; Unknown: 6.2% | Recommended treatment for post-surgery clinically high-risk patients vs observation; Change classification reclassification; Overall: KQ1 Low ROB; KQ2: Serious ROB | GenomeDx Biosciences
Morris, 2021^33^; NA; USA; KQ2; Retrospective comparative cohort before/after initiation | 2015–2018; No VA patients | Localized Prostate cancer patients with CCP results (and mpMRI/US, PI-RADS score) from a single practice; 2 cohorts - one newly diagnosed and one “on AS” | Median age: 68 (IQR 62, 72); Race: NR; Median PSA: 7.6 (IQR 5.4, 11.7); Gleason; <7: 39.6%; 3+4: 40.5%; 4+3: 18.0%; >7: 1.8%; T stage: NR | Median Prolaris score −0.5 (IQR −0.9, 0.0); Biopsy; NCCN:; Low: 32.9%; Favorable Intermediate: 24.3%; Unfavorable Intermediate: 34.7%; High: 8.1% | Treatment selection (binary AS or definitive treatment, definitive treatment includes ADR, radiation and or RP); Overall: Moderate ROB | NR
Murphy, 2021^23^; Illinois; KQ1; KQ2; Randomized trial; 200 | Not disclosed; Some VA p atients | Men with new diagnosis of low to favorable intermediate-risk prostate cancer | Median age: 63.6 (6.6); Race; Black: 70.0%; European American: 16.5%; Hispanic or Latino: 12.5%; Asian: 1.0%; PSA: 5.98 (SD 2.44); Gleason; (3+3): 81%; (3+4): 19%; T stage: NR | Median Oncotype: NR; Biopsy; NCCN; Very low: 40%; Low: 35%; Low intermediate: 25% | Proportion choosing active surveillance; Change classification; Overall: High ROB | Biomarker Development Award, DOD, Prostate cancer Research Program
Nguyen, 2017a^55^; Boston, MA; Baltimore, MD; Ann Arbor, MI; San Diego, CA; San Francisco; CA; Cleveland, OH; Houston, TX; Miami, FL; KQ3; Retrospective observational | 1987–2014; No VA patients | Two cohorts were selected: Patients with intermediate or high risk NCCN prostate carcinoma treated with first line RT and/or ADT. Patients of prostate carcinoma with a dverse pathology on RP | Median 64 (IQR 58, 70); Race:; Black: 14%; Arabic: 0.43%; Asian: 1.7%; White: 71%; Hispanic: 1.3%; Other: 12%; PSA: 7 (IQR 4.6, 13.2); Gleason; Grade group 1 19%; Grade group 2 28%; Grade group 3: 25%; Grade group 4: 14%; Grade group 5: 15%; T stage; ≤T1c: 46%; ≥T2a: 53%; Unknown: 0.85% | Median Decipher: 0.39; Biopsy; NCCN; Low: 11%; Intermediate: 54%; High: 32%; Unknown: 3% | Metastasis-free survival; Overall: High ROB | GenomeDx Biosciences, The Wood Foundation, Freeman Family, Fitz’s Cancer Warriors, David and Cynthia Chapin, Hugh Simons in honor of Frank and Anne Simons, The Campbell Family in Honor of Joan Campbell, Scott Forbes and Gina Ventre Fund, the Baker Family, Prostate Cancer Foundation, and a Grant from an Anonymous Family Foundation.
Nguyen, 2017b^58^; NA; Boston, MA, USA; KQ3; Retrospective observational | 2001–2013; No VA patients | Patient with intermediate and high risk NCCN prostate carcinoma treated with radiation and ADT | Median: 67 (IQR 60, 71); Race; Black: 16%; White: 79%; Other: 5%; Median PSA: 7.3 (IQR 4.7–14.9); Gleason; ≤6: 7%; 3+4: 23%; 4+3: 36%; 8: 15%; ≥9: 19%; T stage; ≤T2a: 64%; ≥T2b: 35% | Median Decipher: 0.39 (IQR 0.22– 0.61); Biopsy; NCCN; Intermediate: 55%; High: 45% | Biochemical recurrence-free survival; Metastasis-free survival; Overall: Moderate ROB | Anonymous Family Foundation, the Prostate Cancer Foundation, Fitz’s Cancer Warriors, Cynthia and David Chapin, Hugh Simons in Honor of Frank and Anne Simons, The Gina Ventre and Scotty Forbes Fund, The Campbell Family in Honor of Joan Campbell and GenomeDx Biosciences
Nguyen, 2015^28^; Na; Multicenter, USA; KQ2; Deidentified case history review with and without test; 46 | N/A | Physicians responding to emails invitations were eligible for study. Self-identified genitourinary radiation oncologists using ASTRA directory that provide consultation to at least 80 prostate carcinoma patients per year. Urologists were identified using AUA directory that performed at least 40 RPs per year | Median age 61 (IQR NR); Race: NR; PSA; <10: 90.0%; ≥10: 9.1%; Gleason; 6: 18.2%; 3+4: 36.3%; 4+3: 9.1%; 8: 9.1%; 9: 18.2%; 10: 9.1%; T stage:; pT2N0M0: 45.5%; pT3N0M0: 54.5% | Median Decipher: NR; Prostatectomy; D’Amico risk groups; Low: 18.2%; Intermediate: 36.4%; High: 45.4% | Change in management/treatment decision-making; Overall: Moderate ROB | GenomeDx Biosciences and the National Research Council Canada Industrial Research Assistance Program (grant no. 765817). Partial support was also provided by the Prostate Cancer Foundation, David and Cynthia Chapin, Fitz’s Cancer Warriors, Frank and Anne Simons, and a grant from an anonymous family foundation.
Oderda, 2017^21^; NA; Italy; KQ1; Retrospective observational | RPs 2013–2015; No VA patients | Newly diagnosed cases of prostate cancer with analyzed biopsy and had a successful prior RP | Mean age: 67.7 (SD 6.5); Race: NR; PSA 9.6 (SD 12.6); Gleason; 6: 30.8%; 7: 48.0%; 8–10: 21.2%; T stage; T2: 55.8%; T3: 44.2% | Prolaris score −0.16 (0.72); Biopsy; EAU; Low: 25.0%; Intermediate: 46.1%; High: 28.8% | Change classification reclassification; Biochemical recurrence-free survival; Overall: High ROB | NR
Ramotar, 2022^42^; Toronto Canada and Philly US; KQ3; Retrospective observational | N/A; No VA patients | Men diagnosed with prostate cancer, treated with maximal local therapies (RP and PORT), and having pathology slides available for review. | Median age: 61.5 (42, 77.2); Race: NR; Median PSA: 7.6 (0.4, 165.4); Gleason; 1:11.2%; 2: 37.9%; 3: 29.1%; 4–5: 21.8%; Number Missing: 15; T stage: NR | Decipher; Low: 21%; Intermediate: 29%; High: 50%; Biopsy; Prostatectomy; CAPRA-S; 0–2: 10.4%; 3–5: 44.3%; ≥6: 45.4%; Number missing: 119 | Biochemical recurrence-free survival; Overall: High ROB | Internal funding (through department funds).).
Rayford, 2018^25^; NA; USA; KQ1; Retrospective observational | NR | Tissue from urologic oncology community practice in Memphis, TN obtained from biopsy samples. | Median Black age: 66 (61, 71); Median White age: 65 (60, 71); Median Black PSA: 5.6 (4.0, 8.8); Median White PSA: 4.8 (3.6, 6.9); Gleason; <7: 30%; 3+4: 49%; 4+3: 1.9%; >7: 19%; T stage; T1c: 83%; T2: 15% | Median Prolaris (Black): 3.5%; Median Prolaris (White): 3.1%; Biopsy; AUA; Low: 26%; Intermediate: 41%; High: 33% | Change classification reclassification; Overall: Moderate ROB | NR
Ross, 2016a^59^; 3 academic centers and 1 VA (Hopkins, Mayo, T Jeff, and DVAHCS); KQ3; Retrospective observational | 1990–2010; Some VA patients | After radical prostatectomy, patients with adverse pathologic features had adjuvant RT, RT for minimal PSA disease, RT with higher PSA recurrence compared against patients with no RT at all before the d evelopment of metastasis | Median age: 61 (range of IQR 57, 66); Median PSA 8 (range of IQR 5.2, 15.5); Race: NR; Gleason; ≤3+4: 55%; 4+3: 22%; 8: 11%; ≥9: 12%; T stage: NR | Median Decipher: NR; Biopsy; CAPRA-S: NR | Metastasis-free survival; Overall: Moderate ROB | Unclear
Ross, 2016b^61^; NA; USA, Hopkins; KQ3; Retrospective observational; Linked paper: Spratt, 2017^95^ | 1992–2010; No VA patients | Patients post prostatectomy with localized intermediate or high-risk disease, undetectable PSA after surgery, and no postoperative treatment until the development of metastatic disease | Median age: 60 (56, 64); Race; White: 88.8%; Black: 8.1%; Other: 1.9%; Unknown: 1.2%; PSA 9.5 (IQR 6.2, 14.2); Gleason; ≤6: 26.2%; 7: 53.3%; 8: 13.8%; ≥9: 6.2%; T stage: NR | Median Decipher: 0.34 (IQR 0.22, 0.52); Prostatectomy; Clinical risk tool: NR | Metastasis-free survival; Overall: Moderate ROB | Investigator and Genome Dx Bioscience
Seiden, 2021^16^; Brooklyn, New York; KQ1; Retrospective, single Institution; 63 | 2016 –2020; No VA patients | Black men with low or intermediate risk prostate cancer who would otherwise be managed with active surveillance | Median age: 66 (IQR 61, 69); Race: NR; Median PSA 44 (IQR 28, 60); Gleason; 3+3: 76%; 3+4: 24%; T stage; T1a: 17%; T1b: 10%; T1c: 51%; T2a: 6%; T2b: 2%; T2c: 10%; NA: 5% | Median Oncotype: 25% (IQR 19, 34); Biopsy; NCCN; Very low: 11%; Low: 28%; Favorable Intermediate: 49%; Unfavorable Intermediate: 2% | Change classification reclassification; Overall: Moderate ROB | None
Shahait, 2021^37^; NA; KQ1; KQ3; USA; Prospective observational | 2013–2018; No VA patients | Patients with prostate cancer were treated with radical prostatectomy, adverse pathological features and had post prostatectomy genomic classifier test information | Median age: 63.6 (IQR 58, 68); Race: NR; Median PSA: 5.8 (IQR 4.5, 8.48); Gleason; 1: 2%; 2: 52%; 3: 30%; 4:11%; 5: 6%; T score: NR | Median Decipher: 0.59 (IQR 0.41, 0.72); Prostatectomy; Median CAPRA-S: 5 (IQR 3, 6) | Risk Stratification Time to secondary therapy; Overall: Moderate ROB | None
Shangguan, 2020^45^; NA; China; KQ3; Retrospective observational | 2010–2014; No VA patients | Adverse pathology (seminal vesicle invasion, extracapsular extension, positive surgical margins), post radical prostatectomy at a single institution | Median age: 68 (IQR 64, 73); Race: NR; Median PSA: 15.3 (10.3, 26.0); Gleason; ≤6: 26%; 7: 55%; ≥8: 19%; T score: NR | Median Prolaris: 0.45 (IQR 0.3, 1.3); Prostatectomy; CAPRA-S; Low: 10%; Intermediate: 44%; High: 46% | Biochemical recurrence-free survival; Overall: High ROB | National natural science foundation of China; shanghai municipal education commission-gaofeng clinical medicine grant support
Shore, 2016^35^; USA; KQ2; Prospective registry before/after test; 1596 | Not reported; No VA patients | Patients were newly diagnosed with prostate cancer within the past 6 months, untreated, with sufficient biopsy tissue; presumed clinically localized | Mean age: 65.9 (SD 8.36); Race; Black: 8.9%; Asian: 2.8%; Alaska Native/ Pacific Islander: 0.4%; White: 77%; Latino/Hispanic: 9.1%; Mixed: 0.3%; Other: 0.5%; Unknown: 1.0%; Mean PSA: 7.8 (SD 8.15); Gleason; 6: 47.8%; 3+4: 27.9%; 4+3: 11.9%; 8: 8.3%; ≥9: 4.1%; T stage; T1a: 1.2%; T1b: 0.6%; T1c: 72.1%; T2a: 13.9%; T2b: 6.4%; T2c: 4.7%; T3a: 1.0%; T3b: 0.1% | Mean Prolaris: −0.7 (Range −2.8, 2.0); Biopsy; AUA; Low: 40.2%; Intermediate: 42%; High: 17.7% | Change in management/treatment decision-making; Overall: Moderate ROB | Myriad Genetics
Spratt, 2018a^52^; Houston, Durham, Philly, USA; KQ3; Retrospective observational | 1990 and 2015; Some VA patients | To have undergone RP, sufficient tissue for genomic analysis, and serial PSA measurements post-RP to document undetectable versus persistently detectable PSAs postoperatively | Median age: 60; Race; Black: 21%; White: 73%; Other: 4.6%; Unknown: 0.8%; Median PSA: 6.4; Gleason; 1: 6.7%; 2: 46%; 3: 33%; 4: 7.1%; 5: 6.7%; Unknown: 0.4%; T stage; T2: 48%; T3a: 28%; T3b: 21%; T4: 1.6%; Unknown: 0.8% | Decipher; Low: 46%; Intermediate: 28%; High: 26%; Prostatectomy; CAPRA-S; Low: 26%; Intermediate: 43%; High: 26%; Unknown: 6% | Metastasis-free survival; Overall: Moderate ROB | GenomeDx Biosciences
458 Spratt, 2018b^19^; USA; KQ1; KQ3; Prospective observational; 6,928 | 1997–2016; No VA patients | Patients with either biopsy or radical prostatectomy tissue for localized prostate cancer with exclusion of patients having received neoadjuvant treatment. | Median age: 64 (IQR 58, 70.0); Race; Black: 13.6%; White: 71.1%; Other: 4.2%; Unknown: 11.1%; Median PSA: 7.0 (IQR 4.6, 13.2); Gleason; 3+3: 18.7%; 3+4: 27.7%; 4+3: 25.1%; 8: 13.6%; 9–10: 14.9; T stage; T1: 46%; T2: 44%; T3/4: 8%; Unknown: 1.7% | Median Decipher: NR; Biopsy; Prostatectomy; NCCN; Low: 9%; Intermediate- favorable: 15%; Intermediate-unfavorable: 40%; High/very-high: 35%; Unknown: 1.3% | Change classification reclassification; Metastasis-free survival; Overall: KQ1 Low ROB; KQ3 High ROB | DOD and Prostate Cancer Foundation Young Investigator Award
Tosoian, 2020^43^; NA; USA; KQ3; Retrospective observational | 1995–2005; Some VA patients | NCCN high-risk and VHR who underwent GC testing; high risk = T3a or GG 4–5 or PSA >20; VHR = T3b-T4 or Gleason pattern 5; no neoadjuvant ADT or evidence nodal disease p rior to RP | Median age: 62 (IQR 56, 69); Race: NR; Median PSA 15.2 (6.37, 25.8); Gleason; 1: 14.6%; 2: 13.6%; 3: 8.9%; 4: 35.8%; 5: 22.5%; Unavailable: 4.7%; T stage; T1: 27.7%; T2: 48.1%; T3/4: 17.8%; Unavailable: 6.4% | Decipher; Low: 46.2%; Intermediate: 22.5%; High: 31.4%; Biopsy; Prostatectomy; NCCN; High-risk: 75.8%; Very high-risk: 8.6%; Unavailable: 15.5% | Metastasis-free survival; Overall: Low ROB | Decipher; Biosciences
Tosoian, 2017^56^; USA; KQ3; Retrospective observational; 91; Linked paper: Bishoff 2014^71^ | 1994–2006; VA patients | Patient with NCCN low-risk prostate cancer who underwent radical prostatectomy | Median age: 61.4 (IQR 57, 65.7); Race: NR; Median PSA: 5.7 (4.4, 7.8); Gleason: NR; ≤6: 100%; T stage; T1c: 69.5%; T2a: 24.6%; ≥T2b: 5.6% | Median Prolaris: −0.15 (IQR −0.7, −0.4); Biopsy; CAPRA; Low: 74.6%; Intermediate: 25%; High: 0.4% | Biochemical recurrence-free survival; Overall: High ROB | DOD PRTA award, PCF Young Investigator Award, Patrick Walsh Investigator Grant
Van Den Eeden, 2018^53^; USA, West Coast (CA); KQ3; Cross-sectional; 279 | 1995–2010; No VA patients | Men who had radical prostatectomy with sufficient follow up underwent GPS testing | Median age: 61 (IQR 57, 65); Race; White: 79%; Black: 11%; Other: 10%; PSA 0–4: 9.5%; 4.1–10: 70.1%; ≥10.1: 20.4%; Gleason:; 3+3: 38%; 3+4: 46%; 4+3: 11%; 4+4: 2.7%; Any 5: 2.8%; T stage; T1: 25%; T2: 75%; T3: 0.4% | Median Oncotype: NR; Biopsy; NCCN; Very low: 3%; Low: 21%; Intermediate: 67%; High: 9.3% | Biochemical recurrence-free survival; Metastasis-free survival; Prostate-specific mortality; Overall: Low ROB | Institutional
Vince, 2021^38^; NA; US; KQ3; Prospective observational; 855 | 2015–2019; No VA patients | Clinically localized prostate cancer who underwent testing as part of routine clinical care and were able to be matched with Decipher GRID registry; for AS analysis - clinicians had to have explicitly stated in medical records that AS is primary management strategy and could not have received definitive treatment within 6 months o f diagnosis | Median age 66 (60, 72); Race; Black: 13.1%; Asian: 0.9%; Native American: 0.1%; White: 75%; Unknown/other: 11%; PSA 6.1 (IQR 4.4, 9.2); Gleason; 1: 21.9%; 2: 36%; 3: 23.1%; 4–5: 19%; T stage; T1: 72%; T2: 26.4%; T3/4: 2% | Median Decipher: NR; Biopsy; NCCN; Low: 19.1%; Favorable-intermediate: 30.8%; Unfavorable-intermediate: 40%; High: 10% | Time to Treatment; Time to Treatment Failure; Overall: Low ROB | Blue cross blue shield of Michigan, department of defense physician research training award, Adlfred A Taubman Institute; Prostate cancer Foundation, NCI