# APPENDIX D EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible index prognostic factor, 3=Ineligible comparator prognostic factors, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design.

Citation
Alam, 2019^1^ | 4
Alshalalfa, 2017^2^ | 2
Alshalalfa, 2019^3^ | 3
Anonymous, 2018^4^ | 6
Arsov, 2014^5^ | 1
Beksac, 2018^6^ | 3
Beksac, 2022^7^ | 3
Blume-Jensen, 2015^8^ | 2
Brand, 2016^9^ | 4
Brastianos, 2020^10^ | 3
Canfield, 2018^11^ | 4
Chu, 2021^12^ | 4
Cooperberg, 2018^13^ | 2
Covas Moschovas, 2021^14^ | 4
Creed, 2020^15^ | 2
Cuzick, 2014^16^ | 6
Cuzick, 2021^17^ | 1
Den, 2014^18^ | 4
Den, 2016^19^ | 3
Ding, 2021^20^ | 2
Eggener, 2019^21^ | 4
Falagario, 2019^22^ | 4
Freedland, 2016^23^ | 1
Gaffney, 2021^24^ | 3
Ginsburg, 2021^25^ | 3
Goldberg, 2021^26^ | 4
Greenland, 2020^27^ | 4
Greenland, 2022^28^ | 3
Hall, 2020^29^ | 4
Herlemann, 2020^30^ | 4
Hu, 2018^31^ | 2
Jambor, 2020^32^ | 3
James, 2011^33^ | 1
Jhun, 2017^34^ | 2
Karnes, 2013^35^ | 1
Kim, 2017^36^ | 4
Kim, 2019^37^ | 4
Klein, 2017^38^ | 4
Knudsen, 2016^39^ | 3
Koch, 2016^40^ | 1
Kornberg, 2019^41^ | 4
Lalonde, 2014^42^ | 2
Leapman, 2021^43^ | 3
Lee, 2016^44^ | 4
Lee, 2021^45^ | 4
Lin, 2020^46^ | 4
Lobo, 2015^47^ | 4
Lobo, 2016^48^ | 3
Lonergan, 2020^49^ | 4
Lopez, 2017^50^ | 4
Luca, 2020^51^ | 4
Magi-Galluzzi, 2018^52^ | 3
Mahal, 2018^53^ | 2
Mahal, 2020^54^ | 4
Marascio, 2020^55^ | 4
Marrone, 2015^56^ | 6
Martin, 2019^57^ | 4
Martini, 2019^58^ | 2
Muralidhar, 2019^59^ | 4
Murphy, 2020^60^ | 4
Nguyen, 2018^61^ | 2
Nyame, 2018^62^ | 4
Pardy, 2020^63^ | 3
Pellegrini, 2017^64^ | 2
Prensner, 2014^65^ | 2
Press, 2022^66^ | 4
Purysko, 2019^67^ | 3
Rai, 2019^68^ | 2
Ross, 2014^69^ | 1
Rounbehler, 2018^70^ | 2
Salama, 2013^71^ | 6
Salmasi, 2018^72^ | 4
Shahait, 2021^73^ | 5
Shoag, 2020^74^ | 2
Shore, 2014^75^ | 4
Taylor, 2020^76^ | 3
Tomlins, 2015^77^ | 3
Torres, 2017^78^ | 3
Trabulsi, 2017^79^ | 2
Tward, 2021^80^ | 4
Van den Broeck, 2019^81^ | 3
Whalen, 2016^82^ | 4
White, 2021^83^ | 4
Wibmer, 2019^84^ | 3
Yamoah, 2022^85^ | 3
Zhao, 2016^86^ | 2

## References

1 Alam S, Tortora J, Staff I, Prostate cancer genomics: comparing results from three molecular assays. Canadian Journal of Urology. 2019;26(3):9758–9762.31180305
2 Alshalalfa M, Verhaegh GW, Gibb EA, Low PCA3 expression is a marker of poor differentiation in localized prostate tumors: exploratory analysis from 12,076 patients. Oncotarget. 2017;8(31):50804–50813.28881605
3 Alshalalfa M, Liu Y, Wyatt AW, Characterization of transcriptomic signature of primary prostate cancer analogous to prostatic small cell neuroendocrine carcinoma. International Journal of Cancer. 2019;145(12):3453–3461.31125117
4 Anonymous. NICE Advice - Prolaris gene expression assay for assessing long-term risk of prostate cancer progression: © NICE (2016) Prolaris gene expression assay for assessing long-term risk of prostate cancer progression. BJU International. 2018;122(2):173–180.30134062
5 Arsov C, Jankowiak F, Hiester A, Prognostic value of a cell-cycle progression score in men with prostate cancer managed with active surveillance after MRI-guided prostate biopsy--a pilot study. Anticancer Research. 2014;34(5):2459–66.24778061
6 Beksac AT, Cumarasamy S, Falagario U, Multiparametric Magnetic Resonance Imaging Features Identify Aggressive Prostate Cancer at the Phenotypic and Transcriptomic Level. Journal of Urology. 2018;200(6):1241–1249.30563651
7 Beksac AT, Ratnani P, Dovey Z, Unified model involving genomics, magnetic resonance imaging and prostate-specific antigen density outperforms individual co-variables at predicting biopsy upgrading in patients on active surveillance for low risk prostate cancer. Cancer Reports. 2022;5(3):e1492.34931468
8 Blume-Jensen P, Berman DM, Rimm DL, Development and clinical validation of an in situ biopsy-based multimarker assay for risk stratification in prostate cancer. Clinical Cancer Research. 2015;21(11):2591–600.25733599
9 Brand TC, Zhang N, Crager MR, Patient-specific Meta-analysis of 2 Clinical Validation Studies to Predict Pathologic Outcomes in Prostate Cancer Using the 17-Gene Genomic Prostate Score. Urology. 2016;89:69–75.26723180
10 Brastianos HC, Murgic J, Salcedo A, Determining the Impact of Spatial Heterogeneity on Genomic Prognostic Biomarkers for Localized Prostate Cancer. European Urology Oncology. 2020;27:27.
11 Canfield S, Kemeter MJ, Febbo PG, Balancing Confounding and Generalizability Using Observational, Real-world Data: 17-gene Genomic Prostate Score Assay Effect on Active Surveillance. Reviews in Urology. 2018;20(2):69–76.30288143
12 Chu CE, Alshalalfa M, Sjostrom M, Prostate-specific Membrane Antigen and Fluciclovine Transporter Genes are Associated with Variable Clinical Features and Molecular Subtypes of Primary Prostate Cancer. European Urology. 2021;79(6):717–721.33840559
13 Cooperberg MR, Erho N, Chan JM, The Diverse Genomic Landscape of Clinically Low-risk Prostate Cancer. European Urology. 2018;74(4):444–452.29853306
14 Covas Moschovas M, Chew C, Bhat S, Association Between Oncotype DX Genomic Prostate Score and Adverse Tumor Pathology After Radical Prostatectomy. European Urology Focus. 2021;20:20.
15 Creed JH, Berglund AE, Rounbehler RJ, Commercial Gene Expression Tests for Prostate Cancer Prognosis Provide Paradoxical Estimates of Race-Specific Risk. Cancer Epidemiology, Biomarkers & Prevention. 2020;29(1):246–253.
16 Cuzick J. Prognostic value of a cell cycle progression score for men with prostate cancer. Recent Results in Cancer Research. 2014;202:133–40.24531787
17 Cuzick JM, Stone S, Lenz L, Validation of the cell cycle progression score to differentiate indolent from aggressive prostate cancer in men diagnosed through transurethral resection of the prostate biopsy. Cancer Reports. 2021:e1535.34423592
18 Den RB, Feng FY, Showalter TN, Genomic prostate cancer classifier predicts biochemical failure and metastases in patients after postoperative radiation therapy. International Journal of Radiation Oncology, Biology, Physics. 2014;89(5):1038–1046.25035207
19 Den RB, Santiago-Jimenez M, Alter J, Decipher correlation patterns post prostatectomy: initial experience from 2 342 prospective patients. Prostate Cancer & Prostatic Diseases. 2016;19(4):374–379.27574020
20 Ding YC, Wu H, Davicioni E, Prostate cancer in young men represents a distinct clinical phenotype: gene expression signature to predict early metastases. Journal of Translational Genetics & Genomics. 2021;5:50–61.33928239
21 Eggener S, Karsh LI, Richardson T, A 17-gene Panel for Prediction of Adverse Prostate Cancer Pathologic Features: Prospective Clinical Validation and Utility. Urology. 2019;126:76–82.30611659
22 Falagario UG, Beksac AT, Martini A, Defining Prostate Cancer at Favorable Intermediate Risk: The Potential Utility of Magnetic Resonance Imaging and Genomic Tests. Journal of Urology. 2019;202(1):102–107.30730408
23 Freedland SJ, Choeurng V, Howard L, Utilization of a Genomic Classifier for Prediction of Metastasis Following Salvage Radiation Therapy after Radical Prostatectomy. European Urology. 2016;70(4):588–596.26806658
24 Gaffney C, Liu D, Cooley V, Tumor size and genomic risk in localized prostate cancer. Urologic Oncology. 2021;39(7):434.e17-434.e22.
25 Ginsburg KB, Jacobs JC, Qi J, Impact of Early Confirmatory Tests on Upgrading and Conversion to Treatment in Prostate Cancer Patients on Active Surveillance. Urology. 2021;147:213–222.32946908
26 Goldberg H, Spratt D, Chandrasekar T, Clinical-genomic Characterization Unveils More Aggressive Disease Features in Elderly Prostate Cancer Patients with Low-grade Disease. European Urology Focus. 2021;7(4):797–806.32156491
27 Greenland NY, Cowan JE, Chan E, Prostate biopsy histopathologic features correlate with a commercial gene expression assay's reclassification of patient NCCN risk category. Prostate. 2020;80(16):1421–1428.32946625
28 Greenland NY, Cooperberg MR, Wong AC, Molecular risk classifier score and biochemical recurrence risk are associated with cribriform pattern type in Gleason 3+4=7 prostate cancer. Investigative And Clinical Urology. 2022;63(1):27–33.34983120
29 Hall WA, Fishbane N, Liu Y, Development and Validation of a Genomic Tool to Predict Seminal Vesicle Invasion in Adenocarcinoma of the Prostate. JCO Precision Oncology. 2020;4:1228–1238.35050780
30 Herlemann A, Huang HC, Alam R, Decipher identifies men with otherwise clinically favorable-intermediate risk disease who may not be good candidates for active surveillance. Prostate Cancer & Prostatic Diseases. 2020;23(1):136–143.31455846
31 Hu JC, Tosoian JJ, Qi J, Clinical Utility of Gene Expression Classifiers in Men With Newly Diagnosed Prostate Cancer. JCO Precision Oncology. 2018;2.
32 Jambor I, Falagario U, Ratnani P, Prediction of biochemical recurrence in prostate cancer patients who underwent prostatectomy using routine clinical prostate multiparametric MRI and decipher genomic score. Journal of Magnetic Resonance Imaging. 2020;51(4):1075–1085.31566845
33 James KM, Cowl CT, Tilburt JC, Impact of direct-to-consumer predictive genomic testing on risk perception and worry among patients receiving routine care in a preventive health clinic. Mayo Clinic Proceedings. 2011;86(10):933–40.21964170
34 Jhun MA, Geybels MS, Wright JL, Gene expression signature of Gleason score is associated with prostate cancer outcomes in a radical prostatectomy cohort. Oncotarget. 2017;8(26):43035–43047.28496006
35 Karnes RJ, Bergstralh EJ, Davicioni E, Validation of a genomic classifier that predicts metastasis following radical prostatectomy in an at risk patient population. Journal of Urology. 2013;190(6):2047–53.23770138
36 Kim H, Kalchman I, Santiago-Jimenez M, Transcriptome evaluation of the relation between body mass index and prostate cancer outcomes. Cancer. 2017;123(12):2240–2247.28140459
37 Kim HL, Li P, Huang HC, Validation of the Decipher Test for predicting adverse pathology in candidates for prostate cancer active surveillance. Prostate Cancer & Prostatic Diseases. 2019;22(3):399–405.30542054
38 Klein EA, Santiago-Jimenez M, Yousefi K, Molecular Analysis of Low Grade Prostate Cancer Using a Genomic Classifier of Metastatic Potential. Journal of Urology. 2017;197(1):122–128.27569435
39 Knudsen BS, Kim HL, Erho N, Application of a Clinical Whole-Transcriptome Assay for Staging and Prognosis of Prostate Cancer Diagnosed in Needle Core Biopsy Specimens. Journal of Molecular Diagnostics. 2016;18(3):395–406.
40 Koch MO, Cho JS, Kaimakliotis HZ, Use of the cell cycle progression (CCP) score for predicting systemic disease and response to radiation of biochemical recurrence. Cancer Biomarkers: Section A of Disease Markers. 2016;17(1):83–8.
41 Kornberg Z, Cowan JE, Westphalen AC, Genomic Prostate Score, PI-RADS TM version 2 and Progression in Men with Prostate Cancer on Active Surveillance. Journal of Urology. 2019;201(2):300–307.30179620
42 Lalonde E, Ishkanian AS, Sykes J, Tumour genomic and microenvironmental heterogeneity for integrated prediction of 5-year biochemical recurrence of prostate cancer: a retrospective cohort study. Lancet Oncology. 2014;15(13):1521–1532.25456371
43 Leapman MS, Wang R, Ma S, Regional Adoption of Commercial Gene Expression Testing for Prostate Cancer. JAMA Oncology. 2021;7(1):52–58.33237277
44 Lee HJ, Yousefi K, Haddad Z, Evaluation of a genomic classifier in radical prostatectomy patients with lymph node metastasis. Res Rep Urol. 2016;8:77–84.27419104
45 Lee DI, Shahait M, Dalela D, External validation of genomic classifier-based risk-stratification tool to identify candidates for adjuvant radiation therapy in patients with prostate cancer. World Journal of Urology. 2021;39(9):3217–3222.33388922
46 Lin DW, Zheng Y, McKenney JK, 17-Gene Genomic Prostate Score Test Results in the Canary Prostate Active Surveillance Study (PASS) Cohort. Journal of Clinical Oncology. 2020;38(14):1549–1557.32130059
47 Lobo JM, Dicker AP, Buerki C, Evaluating the clinical impact of a genomic classifier in prostate cancer using individualized decision analysis. PLoS ONE [Electronic Resource]. 2015;10(3):e0116866.25837660
48 Lobo JM, Stukenborg GJ, Trifiletti DM, Reconsidering adjuvant versus salvage radiation therapy for prostate cancer in the genomics era. Journal of Comparative Effectiveness Research. 2016;5(4):375–82.27294829
49 Lonergan PE, Washington SL 3rd, Cowan JE, Risk Factors for Biopsy Reclassification over Time in Men on Active Surveillance for Early Stage Prostate Cancer. Journal of Urology. 2020;204(6):1216–1221.32519915
50 Lopez IH, Parada D, Gallardo P, Prognostic correlation of cell cycle progression score and Ki-67 as a predictor of aggressiveness, biochemical failure, and mortality in men with high-risk prostate cancer treated with external beam radiation therapy. Reports of Practical Oncology & Radiotherapy. 2017;22(3):251–257.28479874
51 Luca BA, Moulton V, Ellis C, Convergence of Prognostic Gene Signatures Suggests Underlying Mechanisms of Human Prostate Cancer Progression. Genes. 2020;11(7):16.
52 Magi-Galluzzi C, Isharwal S, Falzarano SM, The 17-Gene Genomic Prostate Score Assay Predicts Outcome After Radical Prostatectomy Independent of PTEN Status. Urology. 2018;121:132–138.30142405
53 Mahal BA, Yang DD, Wang NQ, Clinical and Genomic Characterization of Low-Prostate-specific Antigen, High-grade Prostate Cancer. European Urology. 2018;74(2):146–154.29478736
54 Mahal BA, Alshalalfa M, Zhao SG, Genomic and clinical characterization of stromal infiltration markers in prostate cancer. Cancer. 2020;126(7):1407–1412.31905251
55 Marascio J, Spratt DE, Zhang J, Prospective study to define the clinical utility and benefit of Decipher testing in men following prostatectomy. Prostate Cancer & Prostatic Diseases. 2020;23(2):295–302.31719663
56 Marrone M, Potosky AL, Penson D, A 22 Gene-expression Assay, Decipher R (GenomeDx Biosciences) to Predict Five-year Risk of Metastatic Prostate Cancer in Men Treated with Radical Prostatectomy. PLoS currents. 2015;7:17.
57 Martin DT, Ghabili K, Levi A, Prostate Cancer Genomic Classifier Relates More Strongly to Gleason Grade Group Than Prostate Imaging Reporting and Data System Score in Multiparametric Prostate Magnetic Resonance Imaging-ultrasound Fusion Targeted Biopsies. Urology. 2019;125:64–72.30552940
58 Martini A, Wang J, Brown NM, A transcriptomic signature of tertiary Gleason 5 predicts worse clinicopathological outcome. BJU International. 2019;124(1):155–162.30825357
59 Muralidhar V, Zhang J, Wang Q, Genomic Validation of 3-Tiered Clinical Subclassification of High-Risk Prostate Cancer. International Journal of Radiation Oncology, Biology, Physics. 2019;105(3):621–627.31271825
60 Murphy AB, Carbunaru S, Nettey OS, A 17-Gene Panel Genomic Prostate Score Has Similar Predictive Accuracy for Adverse Pathology at Radical Prostatectomy in African American and European American Men. Urology. 2020;142:166–173.32277993
61 Nguyen HG, Welty C, Lindquist K, Validation of GEMCaP as a DNA Based Biomarker to Predict Prostate Cancer Recurrence after Radical Prostatectomy. Journal of Urology. 2018;199(3):719–724.28941923
62 Nyame YA, Grimberg DC, Greene DJ, Genomic Scores are Independent of Disease Volume in Men with Favorable Risk Prostate Cancer: Implications for Choosing Men for Active Surveillance. Journal of Urology. 2018;199(2):438–444.28941920
63 Pardy L, Rosati R, Soave C, The ternary complex factor protein ELK1 is an independent prognosticator of disease recurrence in prostate cancer. Prostate. 2020;80(2):198–208.31794091
64 Pellegrini KL, Sanda MG, Patil D, Evaluation of a 24-gene signature for prognosis of metastatic events and prostate cancer-specific mortality. Bju International. 2017;119(6):961–967.28107602
65 Prensner JR, Zhao S, Erho N, RNA biomarkers associated with metastatic progression in prostate cancer: a multi-institutional high-throughput analysis of SChLAP1. Lancet Oncology. 2014;15(13):1469–1480.25456366
66 Press BH, Jones T, Olawoyin O, Association Between a 22-feature Genomic Classifier and Biopsy Gleason Upgrade During Active Surveillance for Prostate Cancer. European Urology Open Science. 2022;37:113–119.35243396
67 Purysko AS, Magi-Galluzzi C, Mian OY, Correlation between MRI phenotypes and a genomic classifier of prostate cancer: preliminary findings. European Radiology. 2019;29(9):4861–4870.30847589
68 Rai R, Yadav SS, Pan H, Epigenetic analysis identifies factors driving racial disparity in prostate cancer. Cancer Reports. 2019;2(2):e1153.32721098
69 Ross AE, Feng FY, Ghadessi M, A genomic classifier predicting metastatic disease progression in men with biochemical recurrence after prostatectomy. Prostate Cancer & Prostatic Diseases. 2014;17(1):64–9.24145624
70 Rounbehler RJ, Berglund AE, Gerke T, Tristetraprolin Is a Prognostic Biomarker for Poor Outcomes among Patients with Low-Grade Prostate Cancer. Cancer Epidemiology Biomarkers & Prevention. 2018;27(11):1376–1383.
71 Salama JK, Freedland S, Gerber L, Cell Cycle Progression (CCP) Score Significantly Predicts PSA Failure After EBRT. International Journal of Radiation Oncology Biology Physics. 2013;87(2):S125–S125.
72 Salmasi A, Said J, Shindel AW, A 17-Gene Genomic Prostate Score Assay Provides Independent Information on Adverse Pathology in the Setting of Combined Multiparametric Magnetic Resonance Imaging Fusion Targeted and Systematic Prostate Biopsy. Journal of Urology. 2018;200(3):564–572.29524506
73 Shahait M, Alshalalfa M, Nguyen PL, Correlative analysis between two commercially available post-prostatectomy genomic tests. Prostate Cancer & Prostatic Diseases. 2021;24(2):575–577.33750906
74 Shoag J, Liu D, Ma X, Prognostic value of the SPOP mutant genomic subclass in prostate cancer. Urologic Oncology. 2020;38(5):418–422.32192889
75 Shore N, Concepcion R, Saltzstein D, Clinical utility of a biopsy-based cell cycle gene expression assay in localized prostate cancer. Current Medical Research & Opinion. 2014;30(4):547–53.24320750
76 Taylor AS, Morgan TM, Wallington DG, Correlation between cribriform/intraductal prostatic adenocarcinoma and percent Gleason pattern 4 to a 22-gene genomic classifier. Prostate. 2020;80(2):146–152.31737920
77 Tomlins SA, Alshalalfa M, Davicioni E, Characterization of 1577 primary prostate cancers reveals novel biological and clinicopathologic insights into molecular subtypes. European Urology. 2015;68(4):555–67.25964175
78 Torres A, Alshalalfa M, Tomlins SA, Comprehensive Determination of Prostate Tumor ETS Gene Status in Clinical Samples Using the CLIA Decipher Assay. Journal of Molecular Diagnostics. 2017;19(3):475–484.
79 Trabulsi EJ, Tripathi SK, Gomella L, Development of a voided urine assay for detecting prostate cancer non-invasively: a pilot study. BJU International. 2017;119(6):885–895.28075510
80 Tward JD, Schlomm T, Bardot S, Personalizing Localized Prostate Cancer: Validation of a Combined Clinical Cell-cycle Risk (CCR) Score Threshold for Prognosticating Benefit From Multimodality Therapy. Clinical Genitourinary Cancer. 2021;19(4):296–304.e3.33608228
81 Van den Broeck T, Moris L, Gevaert T, Validation of the Decipher Test for Predicting Distant Metastatic Recurrence in Men with High-risk Nonmetastatic Prostate Cancer 10 Years After Surgery. European Urology Oncology. 2019;2(5):589–596.31411980
82 Whalen MJ, Hackert V, Rothberg MB, Prospective Correlation between Likelihood of Favorable Pathology on the 17-Gene Genomic Prostate Score and Actual Pathological Outcomes at Radical Prostatectomy. Urology Practice. 2016;3(5):379–386.37592572
83 White C, Staff I, McLaughlin T, Does post prostatectomy decipher score predict biochemical recurrence and impact care? World Journal of Urology. 2021;39(9):3281–3286.33743058
84 Wibmer AG, Robertson NL, Hricak H, Extracapsular extension on MRI indicates a more aggressive cell cycle progression genotype of prostate cancer. Abdominal Radiology. 2019;44(8):2864–2873.31030245
85 Yamoah K, Awasthi S, Mahal BA, Novel Transcriptomic Interactions Between Immune Content and Genomic Classifier Predict Lethal Outcomes in High-grade Prostate Cancer. European Urology. 2022;81(4):325–330.33303244
86 Zhao SG, Chang SL, Spratt DE, Development and validation of a 24-gene predictor of response to postoperative radiotherapy in prostate cancer: a matched, retrospective analysis. Lancet Oncology. 2016;17(11):1612–1620.27743920