# APPENDIX B SEARCH STRATEGIES

## Database: MEDLINE (via Ovid)

Search date: 4/24/2022

Note: Ovid MEDLINE(R) ALL 1946 to April 22, 2022

Search Set | Search Strategy | Results
#1 | exp Prostatic Neoplasms/ OR ((prostate OR prostatic) ADJ5 (cancer OR cancers OR cancerous OR neoplasm OR neoplasms OR neoplasia OR adenocarcinoma OR adenocarcinomas OR carcinoma OR carcinomas OR malignancy OR malignancies OR tumor OR tumors OR tumour OR tumours)).ti,ab,kw,kf. | 189,179
#2 | (decipher OR prolar?s OR “oncotype Dx” OR OncotypeDx OR GPs).ti,ab,kw,kf. | 41,034
#3 | ((genomic OR genomics OR CCP OR cycle cell proliferat* OR cycle cell progression*) ADJ4 (test OR tests OR testing OR biomarker OR biomarkers OR bio-marker OR bio-markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)).ti,ab,kw,kf. | 10,079
#4 | ((tissue-based OR “tissue based” OR tissue?based) ADJ4 (biomarker OR biomarkers OR bio-marker OR bio-markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)).ti,ab,kw,kf. | 412
#5 | exp Biomarkers, Tumor/ AND exp Genomics/ | 5,741
#6 | 2 or 3 or 4 or 5 | 56,616
#7 | 1 and 6 | 1,213
#8 | Limit 7 to da=20100101–20221231 | 1,013
#9 | 8 not (exp animals/ not exp humans/) | 1,008
#10 | 9 not (case reports OR editorial OR letter OR comment OR congress).pt. | 954

## Database: Embase (via Elsevier)

Search date: 4/24/2022

Note: Search from the Results page

Search Set | Search Strategy | Results
#1 | ‘prostate cancer’/exp OR ((prostate OR prostatic) NEAR/5 (cancer OR cancers OR cancerous OR neoplasm OR neoplasms OR neoplasia OR adenocarcinoma OR adenocarcinomas OR carcinoma OR carcinomas OR malignancy OR malignancies OR tumor OR tumors OR tumour OR tumours)):ti,ab,kw | 301,862
#2 | (decipher OR prolar?s OR ‘oncotype Dx’ OR OncotypeDx OR GPs):ti,ab,kw | 56,629
#3 | ((genomic OR genomics OR CCP OR ‘cycle cell proliferation’ OR ‘cycle cell proliferations’ OR ‘cycle cell progression’ OR ‘cycle cell progressions’) NEAR/4 (test OR tests OR testing OR biomarker OR biomarkers OR bio?marker OR bio?markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)):ti,ab,kw | 15,432
#4 | ((‘tissue based’ OR tissue?based) NEAR/4 (biomarker OR biomarkers OR bio?marker OR bio?markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)):ti,ab,kw | 880
#5 | ‘tumor marker’/exp AND ‘genomics’/exp | 2,092
#6 | #2 OR #3 OR #4 OR #5 | 74,019
#7 | #1 AND #6 | 2,101
#8 | #7 AND [01-01-2010]/sd | 1,929
#9 | #8 AND [humans]/lim | 1,847
#10 | #9 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 940

## Database: Web of Science (via Clarivate) – Science Citation Index Expanded (1900 – present) and Social Science Citation Index (1900 – present)

Search date: 4/24/2022

Note: Select indices under 'Editions'; use Advanced Search

Search Set | Search Strategy | Results
#1 | TS=((prostate OR prostatic) NEAR/5 (cancer OR cancers OR cancerous OR neoplasm OR neoplasms OR neoplasia OR adenocarcinoma OR adenocarcinomas OR carcinoma OR carcinomas OR malignancy OR malignancies OR tumor OR tumors OR tumour OR tumours)) | 243,238
#2 | TS=(decipher OR prolaris OR “oncotype Dx” OR OncotypeDx OR GPS) | 100,600
#3 | TS=((genomic OR genomics OR CCP OR “cycle cell proliferation” OR “cycle cell proliferations” OR “cycle cell progression” OR “cycle cell progressions”) NEAR/4 (test OR tests OR testing OR biomarker OR biomarkers OR bio-marker OR bio-markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)) | 13,969
#4 | TS=((tissue-based OR “tissue based”) NEAR/4 (biomarker OR biomarkers OR bio-marker OR bio-markers OR marker OR markers OR classifier OR classifiers OR score OR scores OR scoring OR assay OR assays)) | 477
#5 | #2 OR #3 OR #4 | 114,631
#6 | #1 AND #5 | 1,290
#7 | #7 AND (2022 or 2022 or 2021 or 2020 or 2019 or 2018 or 2017 or 2016 or 2015 or 2014 or 2013 or 2012 or 2011 or 2010 (Publication Years)) | 1,142
#8 | #8 NOT (Meeting Abstracts or Editorial Materials or Book Chapters or Letters or News Items (Exclude – Document Types) | 922