# APPENDIX A GENOMIC CLASSIFIER GUIDELINE TABLES

Organization | Clinical Context in Which Test Is Recommended (eg, Patient Characteristics, Role in Decision Making) | Citation
ASCO | - Active surveillance, prostate cancer; - “Commercially available molecular biomarkers (ie, Oncotype Dx Prostate, Prolaris, Decipher, and Promark) may be offered in situations in which the assay result, when considered as a whole with routine clinical factors, is likely to affect management. Routine ordering of molecular biomarkers is not recommended (Type: Evidence Based; Evidence quality: Insufficient; Strength of recommendation: Moderate)”; - Diagnosis of clinically significant prostate cancer; - “Commercially available molecular biomarkers (ie, Oncotype Dx Prostate, Prolaris, Decipher, and Promark) may be offered in situations in which the assay result, when considered as a whole with routine clinical factors, is likely to affect management. Routine ordering of molecular biomarkers is not recommended (Type: Evidence Based; Evidence quality: Intermediate; Strength of recommendation: Moderate)”; - Postprostatectomy when choosing adjuvant versus salvage radiation; - “The expert panel recommends consideration of a commercially available molecular biomarker (eg, Decipher Genomic Classifier) in situations in which the assay result, when considered as a whole with routine clinical factors, is likely to affect management. In the absence of prospective clinical trial data, routine use of genomic biomarkers in the postprostatectomy setting to determine adjuvant versus salvage radiation or to initiate systemic therapies should not be offered (Type: Evidence-based; Evidence quality: Intermediate; Strength of recommendation: Moderate)” | Molecular Biomarkers in Localized Prostate Cancer: ASCO Guideline; https://ascopubs.org/doi/full/10.1200/JCO.19.02768; Eggener SE, Rumble RB, Armstrong AJ, Morgan TM, Crispino T, Cornford P, van der Kwast T, Grignon DJ, Rai AJ, Agarwal N, Klein EA, Den RB, Beltran H. Molecular Biomarkers in Localized Prostate Cancer: ASCO Guideline. J Clin Oncol. 2020 May 1;38(13):1474–1494. doi: 10.1200/JCO.19.02768. Epub 2019 Dec 12. PMID: 31829902.31829902 31829902
AUA/ ASTRO | - “Clinicians may selectively use tissue-based genomic biomarkers when added risk stratification may alter clinical decision-making. (Expert Opinion)”; - “Clinicians should not routinely use tissue-based genomic biomarkers for risk stratification or clinical decision-making. (Moderate Recommendation; Evidence Level: Grade B); - “the Panel concluded that clinicians should not routinely use tissue-based genomic biomarkers for risk stratification or clinical decision-making; however, clinicians may use such tests selectively when added risk stratification make alter shared decision making.” | Clinically Localized Prostate Cancer: AUA/ASTRO Guideline (2022); https://www.auanet.org/guidelines/guidelines/clinically-localized-prostate-cancer-aua/astro-guideline-2022; Eastham JA, Auffenberg GB, Barocas DA, Clinically localized prostate cancer: AUA/ASTRO guideline, part I: introduction, risk assessment, staging, and risk-based management. J Urol. 2022;208(1):10–18 35536144
NCCN | - “Patients with NCCN low, favorable intermediate, unfavorable intermediate, or high-risk disease and life expectancy ≥10 y may consider the use of the following tumor-based molecular assays: Decipher, Oncotype DX Prostate, and Prolaris.”; - “The Decipher molecular assay is recommended to inform adjuvant treatment if adverse features are found post-radical prostatectomy, and can be considered as part of counseling for risk stratification in patients with PSA resistance/recurrence after radical prostatectomy (category 2B).”; - For Clinically Localized Disease; - All three relevant gene expression tests noted to be recommended for prognostic and not predictive purposes; - Decipher: noted to be trained for distant metastases (level of validation evidence 1); - Prolaris: validated for multiple endpoints but not trained for a specific endpoint (level of validation evidence: 3); - Oncotype: noted to be trained for adverse pathology (level of validation evidence 3) | NCCN Clinical Practice Guidelines: Prostate Cancer Version 1.2023; prostate.pdf (nccn.org) (https://www.nccn.org/professionals/physician_gls/pdf/prostate.pdf)
ESMO | - “Tissue-based molecular assays may be used in conjunction with clinicopathological factors for treatment decision making in localised prostate cancer [IV, C]” | Prostate Cancer: ESMO Clinical Practice Guidelines for diagnosis, treatment and follow-up; https://www.annalsofoncology.org/article/S0923-7534(20)39898-7/fulltext#secsectitle0150

Notes.

a Now called Genomic Prostate Score (GPS) test (MDxHealth).

## Prostate Cancer Genomic Classifiers Summary

| Decipher | Genomic Prostate Score | Prolaris
Specimen type | Biopsy, radical prostatectomy | Biopsy | Biopsy, radical prostatectomy
Assay gene coverage | 22 genes (7 cancer pathways) | 12 prostate cancer related genes and 5 reference genes | 31 CCP genes, 15 reference genes
Scoring | 0–0.45 (Low), 0.45–0.60 (intermediate), and 0.60–1.0 (high) risk; Range 0–1 (higher score=higher risk) | Low, intermediate, and high risk; Range 0–100 (higher score=higher risk) | Majority of scores from 1–11 (higher score=higher risk)
Company | Veracyte | MDxHealth | Myriad Genetics