# ABBREVIATIONS TABLE

ART: Adjuvant radiotherapy
AS: Active surveillance
AUA: American Urological Association
AUC: Area under the curve
BCR: Biochemical recurrence
CCP: Cell cycle progression
CHARMS-PF: Checklist for critical appraisal and data extraction for systematic reviews of prognostic factor studies
CI: Confidence interval
COE: Certainty of evidence
EAU: European Association of Urology
GC: Genomic classifier
GG: Grade group
GPS: Genomic Prostate Score test
HR: Hazard ratio
IQR: Interquartile range
KQ: Key question
MRI: Magnetic resonance imaging
NCCN: National Comprehensive Cancer Network
PICOTS: Population, intervention, comparator, outcome, timing, setting
PORTOS: Post-operative Radiation Therapy Outcomes Score
PSA: Prostate-specific antigen
QUIPS: Quality In Prognosis Studies
ROB: Risk of bias
ROBINS-I: Risk of Bias in Nonrandomized Studies of Interventions
RP: Radical prostatectomy
SRT: Salvage radiotherapy
VHA: Veterans Health Administration