# References

1 Zhang B, Liang L, Chen W, . An Updated Study to Determine Association between Gadolinium-Based Contrast Agents and Nephrogenic Systemic Fibrosis. PLoS One. 2015;10(6):e0129720.26076348
2 Nephrogenic Fibrosing Dermopathy Associated With Exposure to GadoliniumContaining Contrast Agents—St. Louis, Missouri, 2002-2006. MMWR. 2007;56:137-141. JAMA. 2007;297(14):1542–1544.
3 Leyba K, Wagner B. Gadolinium-based contrast agents: why nephrologists need to be concerned. Curr Opin Nephrol Hypertens. 2019;28(2):154–162.30531473
4 U.S. Food and Drug Administration. FDA Drug Safety Communication: New warnings for using gadolinium-based contrast agents in patients with kidney dysfunction. Available at: https://www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-new-warnings-using-gadolinium-based-contrast-agents-patients-kidney#sa. Accessed July 30, 2019.
5 McDonald RJ, Levine D, Weinreb J, . Gadolinium Retention: A Research Roadmap from the 2018 NIH/ACR/RSNA Workshop on Gadolinium Chelates. Radiology. 2018;289(2):517–534.30204075
6 Bernstein EJ, Schmidt-Lauber C, Kay J. Nephrogenic systemic fibrosis: a systemic fibrosing disease resulting from gadolinium exposure. Best Pract Res Clin Rheumatol. 2012;26(4):489–503.23040363
7 Schieda N, Maralani PJ, Hurrell C, . Updated Clinical Practice Guideline on Use of Gadolinium-Based Contrast Agents in Kidney Disease Issued by the Canadian Association of Radiologists. Can Assoc Radiol J. 2019;70(3):226–232.31255393
8 Grebe SO, Borrmann M, Altenburg A, . Chronic inflammation and accelerated atherosclerosis as important cofactors in nephrogenic systemic fibrosis following intravenous gadolinium exposure. Clin Exp Nephrol. 2008;12(5):403–406.18551245
9 American College of Radiology. Manual on Contrast Media [online]. Available at: https://www.acr.org/Clinical-Resources/Contrast-Manual. Accessed July 30, 2019.
10 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. PLoS Med. 2009;6(7):e1000097.19621072
11 Runge VM. Dechelation (Transmetalation): Consequences and Safety Concerns With the Linear Gadolinium-Based Contrast Agents, In View of Recent Health Care Rulings by the EMA (Europe), FDA (United States), and PMDA (Japan). Invest Radiol. 2018;53(10):571–578.30130320
12 Scott LJ. Gadobutrol: A Review in Contrast-Enhanced MRI and MRA. Clin Drug Investig. 2018;38(8):773–784.
13 Beam AS, Moore KG, Gillis SN, . GBCAs and Risk for Nephrogenic Systemic Fibrosis: A Literature Review. Radiol Technol. 2017;88(6):583–589.28900045
14 Kitajima K, Maeda T, Watanabe S, . Recent topics related to nephrogenic systemic fibrosis associated with gadolinium-based contrast agents. Int J Urol. 2012;19(9):806–11.22571387
15 Zou Z, Zhang HL, Roditi GH, . Nephrogenic systemic fibrosis: review of 370 biopsy-confirmed cases. JACC Cardiovasc Imaging. 2011;4(11):1206–16.22093272
16 Hellman RN. Gadolinium-induced nephrogenic systemic fibrosis. Semin Nephrol. 2011;31(3):310–6.21784280
17 Abu-Alfa AK. Nephrogenic systemic fibrosis and gadolinium-based contrast agents. Adv Chronic Kidney Dis. 2011;18(3):188–98.21531325
18 Mazhar SM, Shiehmorteza M, Kohl CA, . Nephrogenic systemic fibrosis in liver disease: a systematic review. J Magn Reson Imaging. 2009;30(6):1313–22.19937937
19 Chrysochou C, Buckley DL, Dark P, . Gadolinium-enhanced magnetic resonance imaging for renovascular disease and nephrogenic systemic fibrosis: critical review of the literature and UK experience. J Magn Reson Imaging. 2009;29(4):887–94.19306428
20 Runge VM. Advances in magnetic resonance (2008). Invest Radiol. 2008;43(12):893–8.19002061
21 Agarwal R, Brunelli SM, Williams K, . Gadolinium-based contrast agents and nephrogenic systemic fibrosis: a systematic review and meta-analysis. Nephrol Dial Transplant. 2009;24(3):856–63.18952698
22 Nainani N, Panesar M. Nephrogenic systemic fibrosis. Am J Nephrol. 2009;29(1):1–9.18663283
23 Bhave G, Lewis JB, Chang SS. Association of gadolinium based magnetic resonance imaging contrast agents and nephrogenic systemic fibrosis. J Urol. 2008;180(3):830–5; discussion 835.18635232
24 Idee JM, Port M, Medina C, . Possible involvement of gadolinium chelates in the pathophysiology of nephrogenic systemic fibrosis: a critical review. Toxicology. 2008;248(2–3):77–88.18440117
25 Marckmann P. Nephrogenic systemic fibrosis: epidemiology update. Curr Opin Nephrol Hypertens. 2008;17(3):315–9.18408485
26 Anzalone N, Essig M, Lee SK, . Optimizing contrast-enhanced magnetic resonance imaging characterization of brain metastases: Relevance to stereotactic radiosurgery. Neurosurgery. 2013;72(5):691–701.23381488
27 European Medicines Agency. Gadolinium-containing contrast agents. Available at: https://www.ema.europa.eu/en/medicines/human/referrals/gadolinium-containing-contrast-agents. Accessed September 5, 2019.
28 Evidence Partners Inc. DistillerAI website. Available at: https://www.evidencepartners.com/distiller-ai/. Accessed October 12, 2018.
29 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors Accessed May 17, 2018.
30 Evidence Partners. Methods Commentary: Risk of Bias in Cohort Studies. Available at: https://www.evidencepartners.com/resources/methodological-resources/risk-of-bias-in-cohort-studies/. Accessed July 30, 2019.
31 Clopper CJ, Pearson ES. The use of confidence or fiducial limits illustrated in the case of the binomial. Biometrika. 1934;26(4):404–413.
32 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
33 Bryant BJ, 2nd, Im K, Broome DR. Evaluation of the incidence of nephrogenic systemic fibrosis in patients with moderate renal insufficiency administered gadobenate dimeglumine for MRI. Clin Radiol. 2009;64(7):706–13.19520215
34 Gheuens E, Daelemans R, Mesens S. Dialysability of gadoteric acid in patients with end-stage renal disease undergoing hemodialysis. Invest Radiol. 2014;49(8):505–8.24619209
35 Lauenstein T, Ramirez-Garrido F, Kim YH, . Nephrogenic systemic fibrosis risk after liver magnetic resonance imaging with gadoxetate disodium in patients with moderate to severe renal impairment: results of a prospective, open-label, multicenter study. Invest Radiol. 2015;50(6):416–22.25756684
36 Michaely HJ, Aschauer M, Deutschmann H, . Gadobutrol in Renally Impaired Patients: Results of the GRIP Study. Invest Radiol. 2017;52(1):55–60.27529464
37 Prince MR, Lee HG, Lee CH, . Safety of gadobutrol in over 23,000 patients: the GARDIAN study, a global multicentre, prospective, non-interventional study. Eur Radiol. 2017;27(1):286–295.26960538
38 Soulez G, Bloomgarden DC, Rofsky NM, . Prospective Cohort Study of Nephrogenic Systemic Fibrosis in Patients With Stage 3-5 Chronic Kidney Disease Undergoing MRI With Injected Gadobenate Dimeglumine or Gadoteridol. AJR Am J Roentgenol. 2015;205(3):469–78.26295633
39 Soyer P, Dohan A, Patkar D, . Observational study on the safety profile of gadoterate meglumine in 35,499 patients: The SECURE study. J Magn Reson Imaging. 2017;45(4):988–997.27726239
40 Tsushima Y, Awai K, Shinoda G, . Post-marketing surveillance of gadobutrol for contrast-enhanced magnetic resonance imaging in Japan. Jpn J Radiol. 2018;36(11):676–685.30232584
41 Young LK, Matthew SZ, Houston JG. Absence of potential gadolinium toxicity symptoms following 22,897 gadoteric acid (Dotarem(R)) examinations, including 3,209 performed on renally insufficient individuals. Eur Radiol. 2018.
42 McKinney AM, Gawande R, Pezeshk P, . Preliminary experience with intravenous gadoxetate disodium as a craniospinal MR contrast agent. Eur J Radiol. 2015;84(12):2539–47.26456308
43 Nandwana SB, Moreno CC, Osipow MT, . Gadobenate Dimeglumine Administration and Nephrogenic Systemic Fibrosis: Is There a Real Risk in Patients with Impaired Renal Function? Radiology. 2015;276(3):741–7.25875973
44 Shaffer KM, Parikh MR, Runge TM, . Renal safety of intravenous gadolinium-enhanced magnetic resonance imaging in patients awaiting liver transplantation. Liver Transpl. 2015;21(11):1340–6.25786913
45 de Campos RO, Heredia V, Ramalho M, . Quarter-dose (0.025 mmol/kg) gadobenate dimeglumine for abdominal MRI in patients at risk for nephrogenic systemic fibrosis: preliminary observations. AJR Am J Roentgenol. 2011;196(3):545–52.21343495
46 Abujudeh HH, Rolls H, Kaewlai R, . Retrospective assessment of prevalence of nephrogenic systemic fibrosis (NSF) after implementation of a new guideline for the use of gadobenate dimeglumine as a sole contrast agent for magnetic resonance examination in renally impaired patients. J Magn Reson Imaging. 2009;30(6):1335–40.19937927
47 Reilly RF. Risk for nephrogenic systemic fibrosis with gadoteridol (ProHance) in patients who are on long-term hemodialysis. Clin J Am Soc Nephrol. 2008;3(3):747–51.18287249
48 Deray G, Rouviere O, Bacigalupo L, . Safety of meglumine gadoterate (Gd-DOTA)-enhanced MRI compared to unenhanced MRI in patients with chronic kidney disease (RESCUE study). Eur Radiol. 2013;23(5):1250–9.23212275
49 Bruce R, Wentland AL, Haemel AK, . Incidence of Nephrogenic Systemic Fibrosis Using Gadobenate Dimeglumine in 1423 Patients With Renal Insufficiency Compared With Gadodiamide. Invest Radiol. 2016;51(11):701–705.26885631
50 Smorodinsky E, Ansdell DS, Foster ZW, . Risk of nephrogenic systemic fibrosis is low in patients with chronic liver disease exposed to gadolinium-based contrast agents. J Magn Reson Imaging. 2015;41(5):1259–67.24811860
51 Amet S, Launay-Vacher V, Clement O, . Incidence of nephrogenic systemic fibrosis in patients undergoing dialysis after contrast-enhanced magnetic resonance imaging with gadolinium-based contrast agents: the Prospective Fibrose Nephrogenique Systemique study. Invest Radiol. 2014;49(2):109–15.24169070
52 Becker S, Walter S, Witzke O, . Application of gadolinium-based contrast agents and prevalence of nephrogenic systemic fibrosis in a cohort of end-stage renal disease patients on hemodialysis. Nephron Clin Pract. 2012;121(1–2):c91–4.23182840
53 Elmholdt TR, Pedersen M, Jorgensen B, . Nephrogenic systemic fibrosis is found only among gadolinium-exposed patients with renal insufficiency: a case-control study from Denmark. Br J Dermatol. 2011;165(4):828–36.21692765
54 Martin DR, Krishnamoorthy SK, Kalb B, . Decreased incidence of NSF in patients on dialysis after changing gadolinium contrast-enhanced MRI protocols. J Magn Reson Imaging. 2010;31(2):440–6.20099361
55 Chrysochou C, Power A, Shurrab AE, . Low risk for nephrogenic systemic fibrosis in nondialysis patients who have chronic kidney disease and are investigated with gadolinium-enhanced magnetic resonance imaging. Clin J Am Soc Nephrol. 2010;5(3):484–9.20093350
56 Zou Z, Ma L, Li H. Incidence of nephrogenic systemic fibrosis at Chinese PLA General Hospital. J Magn Reson Imaging. 2009;30(6):1309–12.19937931
57 Hoppe H, Spagnuolo S, Froehlich JM, . Retrospective analysis of patients for development of nephrogenic systemic fibrosis following conventional angiography using gadolinium-based contrast agents. Eur Radiol. 2010;20(3):595–603.19760239
58 Janus N, Launay-Vacher V, Karie S, . Prevalence of nephrogenic systemic fibrosis in renal insufficiency patients: results of the FINEST study. Eur J Radiol. 2010;73(2):357–9.19128909
59 Prince MR, Zhang H, Morris M, . Incidence of nephrogenic systemic fibrosis at two large medical centers. Radiology. 2008;248(3):807–16.18710976
60 Schieren G, Tokmak F, Lefringhausen L, . C-reactive protein levels and clinical symptoms following gadolinium administration in hemodialysis patients. Am J Kidney Dis. 2008;51(6):976–86.18501785
61 Cowper SE, Rabach M, Girardi M. Clinical and histological findings in nephrogenic systemic fibrosis. Eur J Radiol. 2008;66(2):191–9.18325705
62 Endrikat J, Dohanish S, Schleyer N, . 10 Years of Nephrogenic Systemic Fibrosis: A Comprehensive Analysis of Nephrogenic Systemic Fibrosis Reports Received by a Pharmaceutical Company from 2006 to 2016. Invest Radiol. 2018;53(9):541–550.29547493
63 Lohani S, Golenbiewski J, Swami A, . A unique case of nephrogenic systemic fibrosis from gadolinium exposure in a patient with normal eGFR. BMJ Case Rep. 2017;2017.
64 Barbieri S, Schroeder C, Froehlich JM, . High signal intensity in dentate nucleus and globus pallidus on unenhanced T1-weighted MR images in three patients with impaired renal function and vascular calcification. Contrast Media Mol Imaging. 2016;11(3):245–50.26929131
65 Birka M, Wentker KS, Lusmoller E, . Diagnosis of nephrogenic systemic fibrosis by means of elemental bioimaging and speciation analysis. Anal Chem. 2015;87(6):3321–8.25708271
66 Elmholdt TR, Olesen AB, Jorgensen B, . Nephrogenic systemic fibrosis in Denmark--a nationwide investigation. PLoS One. 2013;8(12):e82037.24349178
67 Becker S, Walter S, Witzke O, . The German registry for nephrogenic systemic fibrosis: findings from 23 patients. Clin Nephrol. 2010;73(6):426–30.20497754
68 Wollanka H, Weidenmaier W, Giersig C. NSF after Gadovist exposure: a case report and hypothesis of NSF development. Nephrol Dial Transplant. 2009;24(12):3882–4.19767635
69 Shin K, Granter SR, Coblyn JS, . Progressive arm and leg stiffness in a patient with chronic renal impairment. Nat Clin Pract Rheumatol. 2008;4(10):557–62.18711420
70 Sadowski EA, Bennett LK, Chan MR, . Nephrogenic systemic fibrosis: risk factors and incidence estimation. Radiology. 2007;243(1):148–57.17267695
71 Semelka RC, Commander CW, Jay M, . Presumed Gadolinium Toxicity in Subjects With Normal Renal Function: A Report of 4 Cases. Invest Radiol. 2016;51(10):661–5.27548344
72 Papanicolas I, Woskie LR, Jha AK. Health Care Spending in the United States and Other High-Income Countries. JAMA. 2018;319(10):1024–1039.29536101
73 Attari H, Cao Y, Elmholdt TR, . A Systematic Review of 639 Patients with Biopsy-confirmed Nephrogenic Systemic Fibrosis. Radiology. 2019;292(2):376–386.31264946
74 Perez-Rodriguez J, Lai S, Ehst BD, . Nephrogenic systemic fibrosis: incidence, associations, and effect of risk factor assessment-report of 33 cases. Radiology. 2009;250(2):371–7.19188312
75 Chou R, Helfand M. Challenges in systematic reviews that assess treatment harms. Ann Intern Med. 2005;142(12 Pt 2):1090–9.15968034
76 Chou R, Aronson N, Atkins D, . AHRQ series paper 4: assessing harms when comparing medical interventions: AHRQ and the effective health-care program. J Clin Epidemiol. 2010;63(5):502–12.18823754
77 Davenport MS. Virtual Elimination of Nephrogenic Systemic Fibrosis: A Medical Success Story with a Small Asterisk. Radiology. 2019;292(2):387–389.31268818
78 Endrikat J, Vogtlaender K, Dohanish S, . Safety of Gadobutrol: Results From 42 Clinical Phase II to IV Studies and Postmarketing Surveillance After 29 Million Applications. Invest Radiol. 2016;51(9):537–43.26964075
79 Voth M, Rosenberg M, Breuer J. Safety of gadobutrol, a new generation of contrast agents: experience from clinical trials and postmarketing surveillance. Invest Radiol. 2011;46(11):663–71.21623211
80 U.S. Food and Drug Administration. FDA Adverse Event Reporting System (FAERS) Public Dashboard. Available at: https://www.fda.gov/drugs/questions-and-answers-fdas-adverse-event-reporting-system-faers/fda-adverse-event-reporting-system-faers-public-dashboard. Accessed August 23, 2019.
81 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration. Chapter 8: Assessing risk of bias in included studies. Available at: https://handbook-5-1.cochrane.org/chapter_8/8_assessing_risk_of_bias_in_included_studies.htm. Accessed September 5, 2019.
82 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
83 Elmholdt TR, Jorgensen B, Ramsing M, . Two cases of nephrogenic systemic fibrosis after exposure to the macrocyclic compound gadobutrol. NDT Plus. 2010;3(3):285–287.28657062
84 Glutig K, Bhargava R, Hahn G, . Safety of gadobutrol in more than 1,000 pediatric patients: subanalysis of the GARDIAN study, a global multicenter prospective non-interventional study. Pediatr Radiol. 2016;46(9):1317–23.27041276