# Acknowledgments

This topic was developed in response to a nomination by Patrick Pun, Medical Director, Dialysis Unit, Durham VA Medical Center, for the purpose of guiding the Nephrology Field Advisory Committee’s recommendations for development of national and local policies. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Patrick Pun, MD, MHS
  VHA Renal Field Advisory Committee
  Medical Director, Dialysis Unit
  Durham VA Medical Center
- Susan Crowley, MD, FASN
  VHA National Program Director for Kidney Disease
  Chief, Renal Section
  VA Connecticut Healthcare System

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Brent Wagner, MD, MS, FACP, FASN
  Acting Associate Chief of Staff, Research
  New Mexico VA Health Care System
  Associate Professor of Medicine
  University of New Mexico
- Clare Haystead, MD
  Radiologist, Radiology Service
  Durham, VA Medical Center
  Assistant Professor of Radiology
  Duke University
- Roger Chou, MD
  Director of the Pacific Northwest Evidence-based Practice Center
  Professor of Medicine
  Oregon Health & Science University
- Ira Krefting, MD
  Deputy Director for Safety
  Division Medical Imaging Products
  Office of Drug Evaluation
  US Food and Drug Administration

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.