# Summary and Discussion

Magnetic resonance imaging (MRI) has become an essential tool in the diagnosis and management of a myriad of medical conditions, with 118 MRIs per 1,000 people conducted annually in the United States.^72^ Because the preferred contrast medium for MRIs is a gadolinium-based contrast agent (GBCA), there has been widespread exposure to GBCAs across the population. However, with the recognition of the association of GBCA exposure with the rare, but devastating, condition of nephrogenic systemic fibrosis (NSF) among patients with impaired kidney function, swift restrictions were placed on GBCA use for at-risk patients. Currently, GBCA-enhanced MRIs are contraindicated for individuals with acute kidney injury, estimated glomerular filtration rate (eGFR) <30 mL/min/1.73m^2^, and those requiring renal replacement (ie, peritoneal dialysis or hemodialysis) (see Appendix B for guidelines). Fortunately, transition to macrocyclic and newer linear agents, caution with dosing, and judicious use among at-risk individuals have resulted in a dramatically reduced NSF incidence.^73^ However, clinicians caring for patients with kidney disease now face a difficult dilemma. When a patient with impaired renal function could benefit from a GBCA-enhanced MRI and a reasonable alternative is not available, the patient and clinician must determine if the clinical benefit outweighs the small but serious risk of NSF. Given the relative paucity of information about risk of NSF with newer GBCAs in patients with CKD, uncertainty about current restrictions has arisen. Thus, we sought to assess the occurrence of NSF in patients after index exposure to this group of newer, seemingly safer, group of GBCAs.

Among older GBCAs, NSF is a rare adverse event in the range of 36.5 per 100,000 exposures.^74^ However, since the FDA and other international governing bodies issued warnings on the use of these older ACR group I gadolinium agents, there has been a dramatic reduction in NSF occurrence.^1^ While this represents a marked policy success, a resulting implication of this wholesale practice change is that there are fewer opportunities for cases to occur^1^ and less data from which to determine the pools of patients who are at greatest risk and those who can undergo exposure with less risk. Studying adverse events in general can be challenging as they are usually not subjected to the same rigor and systematic collection as other outcomes in clinical trials.^75,76^ Infrequent adverse events, such as NSF, are particularly unlikely to be adequately captured in the context of a trial.

To assess the risk of NSF after exposure to newer linear and macrocyclic GBCAs, we cast a wide net for study types that could provide evidence to explore our key questions, with a primary focus on studies that allowed for calculation of risk with a clear numerator and denominator. However, we also included case series and case reports to provide information about a potential signal for NSF risk not otherwise captured in the identified observational studies. In total, we identified 28 studies for this review. Sixteen studies evaluated only the newer linear or macrocyclic GBCAs (ACR groups II and III) and were included in the analysis to address KQ 1. Twelve studies included patients exposed to both the newer and older linear GBCAs and thus were included in the analysis for KQ 2.

## Summary of Evidence by Key Question

### Key Question 1 Summary

The primary objective of KQ 1 was to identify the occurrence of NSF following index exposure to the presumably safer macrocyclic and newer linear GBCAs (ACR groups II and III). Additionally, our secondary objective was to identify the occurrence of NSF within specific subpopulations: all patients without restriction by kidney function; patients with CKD or AKI; and patients with CKD risk factors such as hypertension and diabetes. We included 16 eligible studies consisting of 15 cohort studies, and 1 nonrandomized controlled trial. Across these studies, ROB was mostly high or unclear. The pooled patient population in the mostly prospective cohort studies was 80,932. Index GBCA exposure was to the newer linear GCBAs in most studies (n=13) and less so to macrocyclic agents (n=2). However, 9 studies reported that patients were exposed to multiple GBCAs, including a mix of macrocyclic and newer linear agents.

Across these studies, there were no cases of NSF reported following exposure to the macrocyclic or newer linear GBCAs (ACR group II and III) or a mix of these agents. While these findings were consistent even within patient subpopulations, such as among all patients or those with CKD and AKI, the majority of patients exposed across all 16 studies did not have kidney disease of any type. In fact, less than 10% of patients across these studies were identified to have CKD. In addition, none of the included studies assessed NSF occurrence specifically among patients with CKD risk factors such as hypertension and diabetes, and acute renal failure was inconsistently reported. In summary, we found no evidence of occurrence of NSF across 80,932 patient index exposures to macrocyclic or newer linear GBCAs among patients mostly with normal or near normal renal function. As shown in the forest plot (Figure 3), the exact upper 95% CI for the estimate of NSF occurrence per exposure ranged from 0.0001 to 0.3085. Thus, rare events remain possible in understudied populations (eg, CKD, AKI, and patients at risk for CKD).

This review focused on the development of NSF after index exposure to an ACR group II or III GBCA (KQ 1), and when possible, in comparison to ACR group I GBCAs (KQ 2). For these outcomes, we assessed our degree of confidence in our summary findings using certainty of evidence (COE) ratings. Similar to our analysis, for rating the COE we focused on those studies which were primarily designed to identify NSF after GBCA exposure. We present the COE for each patient population of interest across both KQs. These ratings are summarized below with supporting information provided in Table 10.

- We found low COE due to ROB that there are no cases of NSF after index exposure to ACR group II GBCAs among patients in [underlined: the general population without restriction by] [underlined: kidney function].
- We found low COE due to ROB that there are no cases of NSF after index exposure to ACR group II GBCAs among patients with [underlined: any level of kidney disease].
- We found very low COE due to ROB that there are no cases of NSF after index exposure to ACR group II or III GBCAs among patients with [underlined: stage 3-5 CKD].
- We found low COE due to ROB that there are no cases of NSF after index exposure to ACR group II GBCAs among patients with [underlined: ESRD on dialysis].

Because we found no studies in patient populations with risk factors for CKD, we did not rate the certainty of evidence for this question. In addition, the only patient population in which a study used the ACR group III agent, gadoexetic acid, was CKD stage 3-5, thus that is the only COE rating that includes mention of ACR group III GBCAs.

Table 10 Certainty of Evidence for Occurrence of NSF After Index Exposure to ACR Group II and III GBCAs

Outcome | Number of Studies (Number of Patients) | Range of CI | Certainty of Evidence Rating (Rationale)
Cases of NSF in all levels of kidney function | 3 cohort studies (62,544) | 0 cases of NSF Upper limit 95% CI range: 0.0001 to 0.0011 | 0 Cases of NSF – Low COE (rated down for serious risk of bias)
Cases of NSF in patients with key risk factors for CKD | 0 studies | - | -
Cases of NSF in patients with any level kidney disease | 3 cohort studies (16,471) | 0 cases of NSF Upper limit 95% CI range: 0.0002 to 0.0196 | 0 Cases of NSF – Low COE (rated down for serious risk of bias)
Cases of NSF in patients with CKD stage 3-5^a^ | 6 observational studies^b^ (1,8036) | 0 cases of NSF Upper limit CI range: 0.0111 to 0.0246^b^ | 0 Cases of NSF – Very Low COE (rated down for very serious risk of bias)
Cases of NSF in patients on dialysis | 3 cohort studies (552) | 0 cases of NSF Upper limit CI range: 0.0092 to 0.0385 | 0 Cases of NSF – Low COE (rated down for serious risk of bias)

a Includes one study with 186 patients with index exposure to ACR group III agent.

b Includes 2 cohort studies and 1 nonrandomized controlled study, which are not included in the upper limit 95% CI ranges.

Abbreviations: CI=confidence interval; COE=certainty of evidence; NSF=nephrogenic systemic fibrosis; ROB=risk of bias

### Key Question 2 Summary

We also assessed the occurrence of NSF among patients after index exposure to macrocyclic or newer linear GBCAs (ACR group II/III) compared with older linear GBCAs (ACR group I). Due to heterogeneity of patient populations, methodology, and time frame, we did not conduct meta-analyses or calculate risk ratios. Thus, we conducted a narrative synthesis of the 12 included studies for KQ 2, including 1 nested case-control study and 11 cohort studies. Across these studies, there were 110,345 patient index exposures to ACR group I GBCAs, 8,499 patient index exposures to ACR group II GBCAs, and no patient index exposures to the single ACR group III GBCA, gadoxetic acid. Most cohort studies were retrospective and reviewed existing chart records and administrative databases with occasional supplementation by provider recall. The majority of the patient-level index exposures across these 12 studies occurred in general patient populations with mostly normal kidney function (112,436 of 118,844, 94.6%). Those studies focused on patients with CKD were grouped by general stage of CKD with 3 studies looking at NSF across any CKD stage, 2 studies focused on patients with stage 3-5 CKD, and 4 studies examining patients on dialysis only (5,427 patient index GBCA exposures). No studies specifically examined patients at risk for CKD.

Of the 41 cases of NSF identified in these 12 studies, only 4 cases were among ACR group II agents, of which 3 appear to be confounded with other unspecified GBCAs. The rest of the NSF cases occurred among patients with reported exposure to ACR group I agents. Among the 4 cases of NSF that occurred after index exposure to ACR group II agents, all had CKD of some stage and 2 had eGFR <30 or were on dialysis. Thus, across studies with 8,499 index exposures to ACR group II patients there was 1 reported unconfounded case of NSF (though this case came from a study that did not report exposures received outside the study institution). The exact upper 95% CI for NSF occurrence per index GBCA exposure for ACR group I agents ranged from 0.0001 to 0.4593 compared to ACR group II agents which ranged from 0.0018 to 0.9750 (see Figure 6). Thus, incident NSF is rare but the confidence intervals for ACR group I and group II agents are similar. The relatively scarce data among patients with CKD and among patients with exposures to the single ACR group III agent limit conclusions that can be drawn about safety and risk in these populations.

As noted above, we also present the COE rating for each patient population of interest. These ratings are summarized below with supporting information provided in Table 11.

- We found very low COE due to ROB and inconsistency that there are 14 cases of NSF after 108,790 index exposures to ACR group I GBCAs compared to 1 case of NSF after 3,646 ACR group II GBCAs among patients in [underlined: all patients without restriction by renal] [underlined: function].
- We found very low COE due to ROB that there are 7 cases of NSF after 629 index exposures to ACR group I or and 3 after 1,675 index exposures group II GBCAs among patients with [underlined: any level of renal insufficiency].
- We found very low COE due to ROB and inconsistency that there are 7 cases of NSF after 272 index exposures to ACR group I and no cases of NSF after 1,424 index exposure to ACR group II GBCAs among patients with [underlined: stage 3-5 CKD].
- We found very low COE due to ROB that there are 9 cases of NSF after 348 index exposures to ACR group I GBCAs compared to 0 cases of NSF after 1,079 index exposures to ACR group II GBCAs among patients with [underlined: ESRD on dialysis].

Similar to KQ 1, we found no studies in patient populations with risk factors for CKD, we did not rate the certainty of evidence for this question. We also did not find any studies that included exposures to ACR group III GBCAs.

Table 11 Certainty of Evidence for Occurrence of NSF After Index Exposure to ACR Group II Compared With ACR Group I GBCAs

Outcome | Number of Studies (Number of Patients) | Number of Cases NSF Range of CI | Certainty of Evidence Rating (Rationale)
Cases of NSF in all patients | 2 cohort studies; (112,436) | 14 cases NSF after 108,790 ACR group I GBCA exposures; Upper limit CI range: 0.0001 to 0.0003 | Very Low COE (rated down for very serious risk of bias and inconsistency)
Cases of NSF in all patients | 2 cohort studies; (112,436) | 1 case NSF after 3,646 ACR group II GBCA exposures; Upper limit CI range 0.0018 to 0.0058 | Very Low COE (rated down for very serious risk of bias and inconsistency)
Cases of NSF in patients with key risk factors for CKD | 0 studies | - | -
Cases of NSF in patients with any level of kidney disease | 3 observational studies (2,304) | 7 cases NSF after 629 ACR group I GBCA exposures^a^; Upper limit CI range: 0.0065 to 0.0672 | Very Low COE (rated down for very serious risk of bias)
Cases of NSF in patients with any level of kidney disease | 3 observational studies (2,304) | 3 case NSF after 1,675 ACR group II GBCA exposures^a^; Upper limit CI range 0.0025 to 0.0204 | Very Low COE (rated down for very serious risk of bias)
Cases of NSF in patients with CKD stage 3-5 | 2 cohort studies (1,696) | 7 cases NSF after 272 ACR group I GBCA exposures; Upper limit CI range:0.0523 to 0.1964 | Very Low COE (rated down for very serious risk of bias and inconsistency)
Cases of NSF in patients with CKD stage 3-5 | 2 cohort studies (1,696) | 0 case NSF after 1,424 ACR group II GBCA exposures; Upper limit CI range 0.0026 to 0.9750 | Very Low COE (rated down for very serious risk of bias and inconsistency)
Cases of NSF in patients on dialysis | 4 cohort studies (1,427) | 9 cases NSF after 348 ACR group I GBCA exposures; Upper limit CI range: 0.0499 to 0.4593^b^ | Very Low COE (rated down for very serious risk of bias)
Cases of NSF in patients on dialysis | 4 cohort studies (1,427) | 0 case NSF after 1,079 ACR group II GBCA exposures; Upper limit CI range 0.0047 to 0.2316 | Very Low COE (rated down for very serious risk of bias)

a All 10 were from the case-control study,^53^ which were not included in the upper limit 95% CI ranges.

b One case of NSF was reported in a cohort study where NSF was not a primary outcome,^59^ which were not included in the upper limit 95% CI ranges.

Abbreviations: CI=confidence interval; COE=certainty of evidence; NSF=nephrogenic systemic fibrosis; ROB=risk of bias

### Prior Systematic Reviews

Our findings are generally consistent with prior reviews of NSF risk and GBCA exposure. A recent review by Attari and colleagues (2019)^73^ examined clinical features and risk factors of confirmed NSF cases in addition to comparing the incidence of NSF before and after 2008 (date FDA issued the boxed warning). They derived the denominator for incidence rate calculations from assumptions about market share for GBCAs by ACR group. An accompanying editorial noted the importance of use of a reliable exposure denominator and control group in order to apply data to clinical decision making.^77^ In this project, we prioritized studies that included a clear denominator for patient exposure by GBCA (both KQ 1 and KQ 2) and those that included a comparison to ACR group I GBCAs (KQ 2). (Of note, Attari and colleagues reported 2 cases of unconfounded NSF after ACR group II GBCA exposure, both of which were included in our review under the case report/case series section as well.)

The work by Schieda and colleagues (2019)^7^ as part of the Clinical Practice Guideline from the Canadian Association of Radiologists included a thorough review of reported data around cases of NSF after exposure to individual GBCAs, though it did not summarize the denominator of exposure by agent or group. A review by Zhang and colleagues (2015)^1^ focused on the association between GBCA exposure generally and NSF occurrence and found an odds ratio of 16.504 (95% CI 7.455 to 36.533), which decreased from before 2007 to after 2007. Of their included studies, data by specific individual agents (only gadodiamide, gadopentetate dimeglumine, and gadoterate meglumine) or multiple unspecified agents. Our review included data across all ACR group II and III agents, though we found particularly limited data from ACR group III agents, which is likely a consequence of the restricted indications for its use.^7^ We note that we reviewed the references from identified systematic reviews (those mentioned here and others) as part of our hand-search to supplement those articles identified by our formal search strategy.

## Clinical and Policy Implications

Across 28 studies, we identified few cases—primarily confounded cases—in which group II or III agents were implicated in the development of NSF. Notably, the included studies we identified were heterogeneous in patient population, follow-up length, and overall quality. The majority of patients index GBCA exposures occurred in patients with normal or near normal renal function, and there was relatively little data on other patient populations of interest. Specifically, although several studies included individuals on dialysis, very few adequately reported on acute kidney injury, a known NSF risk factor from prior studies. In addition, there were no studies that specifically examined NSF occurrence among patients at risk for CKD, and few studies provided details on other potential risk factors for NSF development such as modality of renal replacement or inflammation status, among others. Consistent with (guidelines, current VA practice, etc) caution remains prudent in the use of GBCA among individuals with severely impaired renal function (ie, those with eGFR < 30) or fluctuating severe dysfunction and acute kidney injury, as the exact clinical factors contributing to NSF risk in these populations remains unknown (ie, hyperphosphatemia). Further investigation is also warranted to investigate the risk of GBCAs among individuals with kidney transplant and allograft dysfunction.

Canadian guidelines have suggested that individuals with AKI should be managed “similar to those with eGFR <30, with the caveat that if GBCA administration can be delayed it should be until renal function stabilizes or ameliorates.”^7^ Clinical equipoise may be most appropriate during the administration of GBCAs among individuals with AKI given the absence of comprehensive data evaluating NSF risk in this group.

## Limitations

This review has a number of important strengths that provide notable contributions to the literature. First, we used an a priori publicly registered protocol, a comprehensive literature search, and a thorough quality assessment. Second, we focused our review on higher-order evidence that could provide risk calculations. However, in doing so, we may have excluded studies that reported information about NSF cases that may have been related to gadolinium exposure but from which we could not identify a clear numerator and/or denominator. Upon review of excluded studies, the only unconfounded cases of NSF come from 2 papers^78,79^ that describe NSF or NSF-like cases reported to the postmarketing surveillance system of the manufacturer of gadobutrol. While it appears there may be overlap between these papers, together they report 2 to 7 unconfounded cases of NSF (2 of which were already captured in an included study^53^ and 1 in our case reports^68^). In addition, while we included case reports among patients with NSF who were exposed to GBCAs of interest in order to identify a signal for potential risk, we did not include a search of the FDA Adverse Event Reporting database for case reporting.^80^ In addition, it is important to note that this review is not a comprehensive review of all potential harms associated with gadolinium exposure. Of late there has been a growing awareness and concern about the long-term deposition of gadolinium in brain and other tissues among patients with normal renal function.^3,5^ Thus, regardless of the risk of NSF development among certain patient populations, there are other concerns associated with the use of gadolinium that will necessarily inform shared decision-making with patients in need of advanced imaging modalities.

### Study Quality

This report is also limited by the quality of the existing literature. Overall, the risk of bias for included studies was high or unclear primarily due to a few common issues. First, due to both the rarity and severity of NSF, ethical barriers will prevent study of this condition in randomized controlled trials and thus observational studies were the appropriate predominant design of choice for these investigations. Second, assessment of gadolinium exposure was often incomplete due to lack of investigation and accounting for exposures outside the healthcare setting of the study authors. This is particularly problematic in health care contexts such as the United States where patients could potentially receive medical care, and thus contrast-enhanced imaging, in multiple systems simultaneously. If patients had received more gadolinium exposure than captured by the included studies—in particular, if a patient had been exposed to older gadolinium agents with a well-documented risk for NSF—then we would expect that this bias would lead to overestimation of NSF cases. Third, missing data was a common issue. Given the rarity of expected events, if even a few patients who were lost to follow-up had developed NSF, the impact on outcomes would be significant. Thus, incomplete efforts to minimize missing data was a significant quality limitation in some studies and could lead to underestimation of risk of NSF with the agents in question. Fourth, many of the larger, single-agent observational studies included in this review were conducted by the manufacturers of the studied gadolinium agents.^35–40^ As noted above, most of these studies were conducted in response to an FDA mandate for postmarketing surveillance and were powered based on expected incidence rates that turned out to be greater than those observed. This issue was further complicated by the fact that the FDA removed the postmarketing surveillance requirement in the midst of the conduct of some studies and recruitment was subsequently stopped early. Thus, a significant portion of the identified prospective, single-agent observational cohort studies were ultimately underpowered and terminated earlier than planned.

### Publication Bias

Publication bias in the context of rare adverse events can be difficult to identify due to the reliance on observational studies, which are not consistently registered in ClinicalTrials.gov. Entities with a commercial interest in the use of certain gadolinium agents may play a role in potential publication bias—a role that typically is presumed to bias toward publication of favorable results^81^ (or fewer cases of NSF). In the case of GBCA exposure, this risk is somewhat ameliorated by past FDA requirements for such entities to conduct postmarketing surveillance studies, at least some of which resulted in publications identified for this report.^35–40^

### Heterogeneity

In general, the findings across the included studies were consistent with zero or very few cases of NSF reported. This consistency was found despite differences in study design and methodology. Examples of study variability include the severity of renal disease among included patients, country of study conduct, differences in study follow-up duration (see Appendix I), and timing of patient data collection relative to the clinical diagnosis (ie, retrospective vs prospective cohorts). Differences in timing of data collection could be potentially important as some studies obtained data about patient events which occurred before knowledge of NSF was widespread. This timing issue could increase the likelihood of missed or wrong diagnoses. However, Figure 10 shows that the majority of studies reflect patient data from after the initial case reports of NSF.

Figure 10 Study Window Timeline for Included Studies

### Applicability of Findings to the VA Population

Because the currently recognized major determining factors in the pathophysiology of NSF are biological in nature, the results in this report are presumed to be readily applicable to the VA population. In fact, we purposely chose to make eligible those studies that included pediatric populations as we felt that the pathophysiology of NSF would be similar enough to adult populations to provide useful evidence. However, we did find 1 study conducted solely in a VA setting.^47^

## Research Gaps/Future Research

We identified several gaps in the existing literature that warrant further consideration. To systematically identify the existence of, and reason for, these gaps, we used an existing framework (Table 12). Robinson et al^82^ propose the identification of gaps categorically using the PICOTS framework (population, intervention, comparator, outcome, timing, and setting) and classification by reason (insufficient or imprecise information, biased information, inconsistency and/or not the right information).

Table 12 Evidence Gaps and Future Research

Evidence Gap | Reason | Types of Studies to Consider
Population
- No studies conducted specifically among patients with known risk factors for CKD; - Little data among patients with acute kidney injury; - Little data specifically about patients with earlier stage CKD (ie, stage 1-2 CKD); - Need for use of current CKD staging categories (ie, stage 3a/3b); - Only 1 study that specifically focused on Veterans | - Insufficient information; - Not the right information | - Prospective cohort studies; - Retrospective cohort studies; - Postmarket surveillance studies
Interventions
- Understudied GBCAs, specifically gadoexetic acid (Eovist); - Routine and detailed collection of GBCA-exposed history per individual and total cumulative dose per patient; - Consideration of GBCA exposure across health care systems | - Insufficient information; - Biased information | - Prospective cohort studies; - Postmarket surveillance studies
Comparators
- Continued collection of data allowing comparison across different GBCA types (Appendix J) | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies; - Postmarket surveillance studies
Outcomes
- Consistent use of standardized diagnostic criteria for NSF | - Biased information | - Prospective cohort studies; - Postmarket surveillance studies
Setting
- Large, comprehensive health care systems likely to capture majority or all GBCA exposures | - Insufficient information | - Prospective cohort studies; - Retrospective cohort studies

Of note, if there is continued movement to liberalize the use of newer gadolinium agents, prospective monitoring for the development of NSF could support future research on populations at potential risk but who have not previously undergone unrestricted exposure. In addition, the consistent collection of detailed information about potential risk modifiers (eg, inflammatory states,^3^ gadolinium dose, comorbid medication administration) could provide needed data for the identification of factors that promote the development of NSF in some patients with renal disease over others. In particular, prior work has noted that acute kidney injury is a particularly significant risk factor for NSF development. Unfortunately, acute kidney injury was rarely reported across studies and future work may benefit from careful phenotyping of AKI by severity and etiology. Comprehensive national health care systems such as the VA, which provide the majority if not all of an individual patient’s health care, are well-suited to conduct high quality observational studies which capture needed details of gadolinium exposure, relevant risk factors, and use a comprehensive NSF case identification approach including populations of concern such as those with CKD, risk factors for CKD, and AKI.

## Conclusions

Nephrogenic systemic fibrosis is a rare but devastating and usually lethal disease occurring in patients who have received a gadolinium-based contrast agent. Over the last decade, incidence of NSF dropped off dramatically after formal restrictions limited the use of older linear GBCAs, particularly in patients with advanced kidney disease. However, patients with kidney disease and their providers need evidence to guide shared decision-making about the use of newer and seemingly safer GBCAs when MRIs are warranted for clinical care. We found very few cases of NSF reported after index exposures to newer linear and macrocyclic GBCAs. Most reported cases are of uncertain value since they occurred in patients who had also been exposed to other, often older, GBCAs around the same time. Generally, we found little data to inform the care of patients who are at risk for developing CKD or those with acute kidney injury. In addition, most of the data exists among patients with normal renal function and rare cases of NSF cannot be excluded in patients with significant kidney disease.