# Results

## Literature Flow

We identified 2,862 studies through searches of MEDLINE® (via PubMed®), Cochrane Central Register of Controlled Trials (CENTRAL), EMBASE, and Web of Science (Figure 2). An additional 156 articles were identified through reviewing bibliographies of relevant review articles for a total of 3,018 articles. After removing duplicates, there were 1,150 articles. After applying inclusion and exclusion criteria to titles and abstracts, 314 articles remained for full-text review. Of these, 28 unique studies and 10 case reports and case series were retained for data abstraction. The 28 unique studies consisted of 26 cohort studies (10 prospective and 16 retrospective), 1 case control study, and 1 nonrandomized trial. Included studies were conducted across 6 continents, with most taking place in North America, Europe, and Asia. Because of the large number of higher-order evidence studies identified of relevance to the key questions, we have focused the majority of the report on the included cohort, case control, and nonrandomized studies (ie, evidence profile, results, and certainty of evidence) (n=28). We do, however, include a brief summary of the included case series and case studies at the end of the results section.

Figure 2 Literature Flow Chart

* Search results from MEDLINE (637), Embase (307), Web of Science (33), Cochrane (3), and identified from relevant articles (170) were combined.

## Evidence Profile

Table 3 shows the evidence profile of studies included in this systematic review. Appendix G contains detailed study characteristics for the included studies. For a glossary of terms, refer to Appendix H.

Table 3 Evidence Profile for Studies of Gadolinium Agents and NSF

| KQ 1 (N=16) | KQ 2 (N=12)
Study Design | 1 Nonrandomized; 15 Cohort studies | 1 Case-control; 11 Cohort studies
Number of patients | 80,932 | 118,849
Region | 7 USA; 3 Europe; 4 Multi-country; 1 Japan | 7 Europe; 4 USA; 1 China
Median age (range) | 63.3 (49.5 to 72.6); 1 study NR | 59.9 (51.9 to 77); 3 studies NR
Sex % | 52% Women | 12% Women; 2 studies NR
Race % | 11% White; <1% Black; 8 studies NR | <1% White; <1% Black; 11 studies NR
Renal status, n study | 3 All Patients; 3 Any CKD; 6 CKD stage 3-5; 3 Dialysis; 1 Chronic liver disease | 2 All Patients; 3 Any CKD; 2 CKD stage 3-5; 4 Dialysis; 1 Chronic liver disease
Risk factors for CKD | 9 studies NR; 1% hypertension (8 studies reported); 2% diabetes (5 studies reported); 1% prior dialysis (4 studies reported) | 9 studies NR; <1% hypertension (1 study reported); <1% diabetes (2 studies reported); <1% prior dialysis (2 studies reported)
Index gadolinium exposures | Group II: 80,715; Group III: 217 | Group I: 110,345; Group II: 8,499; Other: 5
Risk of bias | [underlined: Overall cohorts]; 9 High; 6 Unclear; 0 Low; [underlined: Nonrandomized trial objective^A^]; 1 High; [underlined: Nonrandomized trial patient-reported^A^]; 1 NA | [underlined: Overall cohorts]; 7 High; 3 Unclear; 1 Low; [underlined: Overall case-control]; 1 Unclear

a The nonrandomized trial was rated for risk of bias for objective outcomes (ie, non–patient-reported outcomes) and patient-reported outcomes (ie, directly reported by the patient without interpretation of the patient’s response). Abbreviations: CKD=chronic kidney disease; NA=not applicable; NR=not reported

## KEY QUESTION 1 When exposed to newer linear gadolinium-based contrast agents (defined as American College of Radiology Group II and III agents), what is the occurrence of nephrogenic systemic fibrosis per index GBCA exposure among

A. All patients without restriction by kidney function
B. Patients with key risk factors for chronic kidney disease (eg, diabetes and hypertension)
C. Patients with any degree of kidney disease (ie, acute kidney injury or chronic kidney disease)

### Key Points

- We identified 15 cohort studies and 1 nonrandomized controlled trial relevant to KQ 1.
- Across all 16 studies, the majority of index GBCA exposures were to ACR group II agents (n=80,715) and fewer to ACR group III agents (n=217).
- Across 3 cohort studies that included 62,544 patients without restricting enrollment to those with CKD, there were no cases of NSF reported (calculated exact upper 95% CI range 0.0001 to 0.0011).
- There were no studies that assessed NSF risk specifically in patients with risk factors for CKD, such as diabetes and hypertension.
- Across 12 studies that included 18,036 patients with any degree of kidney disease (including ESRD on dialysis), no cases of NSF were reported (calculated exact upper 95% CI range 0.0002 to 0.3085).

### Description of Included Studies

Sixteen studies met our inclusion criteria for KQ 1: 8 prospective^33–40^ and 7 retrospective cohort studies,^41–47^ and 1 nonrandomized controlled trial.^48^ Among these studies, 7 were conducted in the United States; 5 were multi-country studies spanning Europe, Asia, and the Americas; 3 were conducted in Europe, and 1 was conducted in Japan. Patients in the cohort studies had exposure to newer linear GBCAs (ACR group II) in 13 studies (gadobenate dimeglumine [n=6], gadobutrol [n=3], gadoterate meglumine [n=3], and gadoteridol [n=1]), and exposure to the macrocyclic agent gadoexetic acid (ACR group III) in 2 studies. Nine of the cohort studies reported exposures to multiple gadolinium agents,^33,35–38,40,43,46,47^ and 7 reported repeated exposures to the same agents.^33–36,38–40^ Eight cohort studies reported the diagnostic approach for NSF, which varied, including review of patients’ medical records (n=3); clinical symptoms and examination of skin lesions (n=1); biopsy (n=1); and the Girardi criteria (n=3). Seven cohort studies were postmarketing surveillance studies funded by GBCA manufacturers.^35–40,48^ In general, risk factors for NSF other than kidney disease were rarely reported.

The nonrandomized controlled trial enrolled patients with stage 3-4 CKD at 4 European sites between 2008 to 2011.^48^ All patients in the exposure arm received the newer linear gadolinium agent, gadoterate meglumine, and were followed for 3 months for the development of NSF (diagnostic approach not reported).

For each of the following KQ subquestions (A-C), we provide narrative descriptions of findings from the relevant included studies. The 13 studies that were primarily designed to identify cases of NSF after GBCA exposure are also included in the forest plot (Figure 3).

### KQ 1A Findings Among Patients Without Restriction by Kidney Function

Three cohort studies recruited patients without restricting enrollment to those who had CKD (1 high, 1 unclear, and 1 low risk of bias [ROB]).^37,39,40^ All were prospective cohort studies conducted as phase 4 postmarketing surveillance studies and were funded by GBCA manufacturers, with a total of 62,544 enrolled patients of whom 1,099had at least moderate CKD (eGFR <60 mL/min/1.73m^2^). Across these 3 studies, there were 27,045 patient index exposures to gadobutrol and 35,499 patient index exposures to gadoterate meglumine. All patients with moderate CKD or worse (eGFR<30 to <60 mL/min/1.73m^2^) underwent a specific safety monitoring period for 3months. There were no cases of NSF reported across these 3 studies (Figure 3, Table 4, and Table 5).

### KQ 1B Findings Among Patients With Key Risk Factors for Chronic Kidney Disease

No studies specifically examined the occurrence of NSF after GBCA exposure among patients with risk factors for CKD. Of the previously described 3 cohort studies, 1 noted the prevalence of concomitant cardiac disease among the 23,708 patients eligible for inclusion to be 5.2%,^37^ and a second study noted that of the 34,474 patients, 4.0% had diabetes mellitus and 4.0% had cardiovascular disease of some type.^39^ The third cohort study did not describe the prevalence of any CKD risk factors.^40^ We identified 1 study that enrolled 352 patients with chronic liver disease awaiting liver transplant, of which 68 had CKD and none were reported to develop NSF.^44^

### KQ 1C Findings Among Patients With Any Degree of Kidney Disease

#### Patients With CKD—Any Stage

For this category, we identified studies that included patients with at least some degree of kidney disease as defined by the study authors. One study rated as unclear ROB evaluated 22,897 MRI examinations in which gadoterate meglumine was administered to adults and children with normal kidney function and those with chronic kidney disease.^41^ Of these exposures, there was clearly reported patient-level data for 15,377 adult patients with stage 1-5 CKD (stages 1/2 defined as eGFR levels ≥60ml/min/1.73m^2^), none of whom were reported to develop NSF over a mean of 6.0 years (range 8 months to 15 years). A second phase 4 postmarketing surveillance cohort study with unclear ROB included 908 patients exposed to gadobutrol (284 with severe CKD or eGFR ≤30 ml/min/1.73m^2^ and 540 with moderate CKD or eGFR ≥30 ml/min/1.73m^2^ and ≤59 ml/min/1.73m^2^) and reported no cases of NSF (Figure 3, Table 4).^36^ One prospective cohort study with high ROB was conducted as a phase 4 study evaluating gadoexetic acid (ie, gadoxetate disodium) among patients with moderate to severe CKD undergoing liver MRI (n=186).^35^

#### Patients With CKD—Stages 3 to 5

Of the 6 identified studies that enrolled patients with stage 3-5 CKD, 3 cohort studies^33,38,46^ (n=887total) were designed to identify cases of NSF after GBCA exposure, and 3^42,45,48^ reported the occurrence of NSF after GBCA exposure as a secondary outcome. Two studies (both with unclear ROB) sought the occurrence of NSF after index exposure to gadobenate dimeglumine at individual medical institutions, 1 among patients with stage 3 CKD only (n=148)^33^ and 1 among patients with stage 3 CKD or worse (n=250).^46^ A second study with high ROB combined data from 2 multicenter prospective cohort postmarketing surveillance studies in which patients with stage 3-5 CKD underwent unconfounded exposure to gadobenate dimeglumine (n=329) or gadoteridol (n=160).^38^ Across the 3 studies reporting NSF as a secondary outcome (2 cohort studies, 1 nonrandomized controlled trial), 31 patients had index exposure to gadoexetic acid,^42^ 25 to quarter-dose gadobenate dimeglumine,^45^ and 70 to gadoterate meglumine.^48^

There were no cases of NSF reported across any of these 6 studies with 1,013 index patient exposures to newer linear or macrocyclic GBCA exposure among patients with stage 3-5 CKD (Figure 3, Table 4, Table 5).

#### Patients With ESRD Receiving Dialysis

In the remaining 3 studies, 2 included patients with ESRD on dialysis^34,47^ and 1 included patients noted to have ESRD or who were undergoing renal transplant evaluation (75.5% were dialysis dependent).^43^ One retrospective cohort study examined 141 Veterans on long-term hemodialysis at the Dallas Veterans Affairs hospital who had undergone a total of 198 exposures to gadoteridol from 2000 to 2007.^47^ A second retrospective cohort study included 401 patients with ESRD or who were undergoing renal transplant evaluation and who underwent index exposure to gadobenate dimeglumine with follow up for a mean of 2.35 years.^43^ Last, 1 study was a phase 1 nonrandomized prospective trial of 10 patients on hemodialysis who received exposure to gadoterate meglumine and then were monitored to identify the rapidity of gadoterate meglumine removal by dialysis and safety for up to 3 months of this GBCA post-exposure.^34^ There were no cases of NSF reported among the 552 patients across these 3 studies who were exposed to newer linear or macrocyclic GBCAs among patients with ESRD or who were undergoing renal transplant evaluation (Figure 3, Table 5).

Figure 3 NSF Occurrence per GBCA Exposure^a^ a The study by Soulez and colleagues has 2 rows depicted, one for each GBCA.^38^

^*^Prospective cohort studies.

Abbreviations: CI=confidence interval; CKD=chronic kidney disease; GBCA=gadolinium-based contrast agent

Table 4 Occurrence of NSF After Index Exposure to ACR Group II and III GBCAs: Cohort Studies

Study | Range Kidney Function Included, N Patients Exposed GFR Range/CKD Stage, N Patients Exposed | Index GBCA (ACR Group) | Number of NSF Cases
All Patients Without Restriction by Kidney Function
Tsushima, 2018^40^ | All = 3,337; eGFR ≥90 mL/min = 728; eGFR ≥60-<90 mL/min = 1587; eGFR 30-59 mL/min = 427; eGFR <30 mL/min = 5 | Gadobutrol (II) | 0
Prince, 2017^37^ | All = 23,708; eGFR 60-90 mL/min = 15; eGFR 30-59 mL/min = 100; eGFR <30 mL/min^a^ = 48 | Gadobutrol (II) | 0
Soyer, 2017^39^ | All = 35,499; eGFR 30-44 mL/min = 417; eGFR 15-30 mL/min = 58; eGFR <15 mL/min = 7 | Gadoterate meglumine (II) | 0
Any Degree of Kidney Disease
Michaely, 2017^36^ | Any degree kidney disease = 908; eGFR >65 mL/min = 38; eGFR >59 and ≤65 mL/min = 46; eGFR ≥30 and ≤ 59 mL/min = 540; eGFR <30 mL/min = 284 | Gadobutrol (II) | 0
Young, 2018^41^ | Any degree kidney disease = 15,377 adults (total = 21,770 adults; 698 children) | Gadoterate meglumine (II) | 0
Lauenstein, 2015^35^ | Any degree kidney disease = 186^b^; eGFR >65 mL/min = 47; eGFR 60-64 mL/min = 32; eGFR 30-59 mL/min = 193; eGFR <30 mL/min^b^ = 85 | Gadoexetic acid (III) | 0
Patients With CKD—Stages 3 to 5
de Campos, 2011^45^ | CKD stages 3-5 = 24 (total 69)^c^; eGFR range < 30 mL/min = 14; eGFR >30 mL/min = 10 | Gadobenate dimeglumine (II) | 0
Soulez, 2015^38^ | CKD stages 3-5 = 329 | Gadobenate dimeglumine (II) | 0
Soulez, 2015^38^ | CKD stages 3-5 = 160 | Gadoteridol (II) | 0
Abujedeh, 2009^46^ | CKD stages 3-5 = 250; Stage 3 = 243; Stage 4 = 6; Acute renal failure = 1 | Gadobenate dimeglumine (II) | 0
Bryant, 2009^33^ | CKD stages 3-5 = 148; mean eCrCl = 50.4 mL/min (range 30-59) | Gadobenate dimeglumine (II) | 0
McKinney, 2015^42^ | CKD stages 3-5 = 31; Mean eGFR = 36.7 mL/min (±18.7) | Gadoexetic acid (III) | 0
Patients With ESRD Receiving Dialysis
Reilly, 2008^47^ | ESRD on dialysis = 141 | Gadoteridol (II) | 0
Nandwana, 2015^43^ | ESRD = 401; ESRD not dialysis dependent = 98; ESRD on dialysis = 303 | Gadobenate dimeglumine (II) | 0
Gheuens, 2014^34^ | ESRD on dialysis = 10 | Gadoterate meglumine (II) | 0
Patients With Chronic Liver Disease
Shaffer, 2015^44^ | Chronic liver disease = 352 | Gadobenate dimeglumine (II) | 0

a Includes those on dialysis.

b Study initially aimed to include only patients with moderate to severe renal insufficiency (eGFR <60); however, some patients had improved eGFR between screening and baseline, so additional categories added; values listed are categorized by baseline eGFR at time point that was most proximal to GBCA exposure. Only 186 of 357 patients completed the 24 month follow-up.

c n = 44 exposed to ½ dose of gadobenate dimeglumine but incomplete data available

Abbreviations: CKD=chronic kidney disease; eCrCl=estimated creatinine clearance; eGFR=estimated glomerular filtration rate; ESRD=end-stage renal disease; GBCA=gadolinium-based contrast agent;; NSF=nephrogenic systemic fibrosis

Table 5 Occurrence of NSF After Index Exposure to ACR Group II and III GBCAs: Nonrandomized Controlled Trial

Study (N patients) | GFR Range/CKD Stage | GBCA (ACR Group) | Number of NSF Cases
Deray, 2013^48^ (n = 135) | Stage 3-4 CKD | Gadoterate meglumine (II) | 0

Abbreviations: CKD=chronic kidney disease; GBCA=gadolinium-based contrast agent; GFR=glomerular filtration rate; NSF=nephrogenic systemic fibrosis

### Quality of Evidence for Key Question 1

Among the cohort studies, ROB was rated high in 9 studies (60%)^34,35,37–39,42,44,45,47^ and unclear in 6 studies (40%) (Figure 4).^33,36,40,41,43,46^ One nonrandomized prospective trial was rated as overall high ROB (Table 6).^48^ While this group of studies shared some common strengths including many being prospective, common factors contributing to higher ROB designations included inadequate or unclear exposure characterization, inadequate outcome identification, and clinically significant rates of missing data. Inadequate or unclear exposure characterization was a frequent finding as many studies did not consider coexisting exposure to GBCAs from institutions or settings outside that of the study activities. Inadequate outcome identification was often due to lack of use of definitive diagnostic criteria or limiting assessment for NSF to a subpopulation of included patients. Rates of missing data was a significant issue, since even the occurrence of a small number of NSF cases would be a clinically significant difference given the low rate of NSF. ROB ratings are shown for each study in Figure 4, Figure 5, and Table 6.

Figure 4 Risk of Bias Ratings for Included Cohort Studies in KQ 1

Figure 5 Risk of Bias Assessment by Question Across Included Cohort Studies in KQ 1

Table 6 Risk of Bias Ratings by Questions for Included Nonrandomized Controlled Trial in KQ 1

ROB Questions | ROB Rating
Random sequence generation (selection bias | High
Allocation concealment (selection bias) | High
Were baseline OUTCOME measurements similar | Low
Were baseline PROVIDER characteristics similar | N/A
Blinding of outcome assessment (detection bias-objective outcome) | Unclear
Blinding of outcome assessment (detection bias-patient-reported outcome) | N/R
Incomplete outcome data (attrition bias) | High
Protection against contamination | Unclear
Selective reporting (reporting bias) | Low
Other bias | Unclear
Overall bias-objective | High
Overall bias-patient-reported | N/A

### Summary of Findings

Overall, there were no cases of NSF reported among the 16 studies that examined the occurrence of NSF among patients exposed to newer linear and macrocyclic GBCAs (ACR groups II and III). Three cohort studies determined rates of NSF following index exposure to macrocyclic or newer linear gadolinium-based agents in all patients, without disaggregation by kidney function or risk factors for CKD (KQ 1A). There were no NSF cases reported in this subpopulation. We did not find studies that assessed NSF risk in patients with key risk factors for CKD such as diabetes and hypertension (KQ 1B). Finally, there were no cases of NSF reported in 12 studies that assessed rates of NSF specifically in patients with any degree of kidney disease (KQ 1C). Of note, among the 10 studies in patients with stage 3 CKD or worse, there were only 1,751 patients with an index ACR group II or III GBCA exposure.

## KEY QUESTION 2 When compared with older gadolinium-based contrast agents (American College of Radiology group I agents), what is the occurrence of nephrogenic systemic fibrosis per index GBCA exposure for newer GBCAs among

A. All patients without restriction by kidney function
B. Patients with key risk factors for chronic kidney disease (eg, diabetes and hypertension)
C. Patients with any degree of kidney disease (ie, acute kidney injury or chronic kidney disease)

### Key Points

- We found 12 studies that examined the occurrence of NSF among patients with index exposure to American College of Radiology (ACR) group I (110,345 patients) and ACR group II GBCAs (8,499 patients), and no exposures to ACR group III GBCAs.
- Across 2 studies enrolling all patients without restriction by renal function, we found 14 cases of NSF after 108,790 ACR group I GBCA exposures (calculated exact upper 95% CI range 0.0001 to 0.0003) and 1 case of NSF after 3,646 ACR group II GBCA exposures (calculated exact upper 95% CI range 0.0018 to 0.0058).
- No studies specifically examined NSF occurrence in patients at risk for CKD.
- Across 9 cohort studies that enrolled patients with any degree of kidney disease (including ESRD on dialysis), 15 cases of NSF were reported after ACR group I GBCA exposures (calculated exact upper 95% CI range 0.0065 to 0.4593), and 0 cases NSF after ACR group II GBCA exposure (calculated exact upper 95% CI range 0.0025 to 0.9750).
- One case control study that enrolled patients with renal insufficiency reported 7 patients with NSF after ACR group I GBCA exposure and 3 after ACR group II GBCA exposure.
- Of the 4 cases of NSF after index exposure to ACR group II agents, 3 appear to be confounded with other GBCAs.

### Description of Included Studies

To address KQ 2, we searched the literature for studies including patients exposed to older linear GBCAs (ACR group I agents) and patients exposed to macrocyclic or newer linear GBCAs (ACR group II and III agents). In total, we found 12 studies that met this criteria (118,844 patients).^49–60^ One was a nested case-control study of NSF cases compared with GBCA-exposed controls. We found 2 retrospective cohort studies that compared the risk of NSF after exposure to gadodiamide (ACR group I) versus gadobenate dimeglumine (ACR group II) before and after multifaceted health care system-level changes to reduce occurrence of NSF; examples of such changes include changing the standard gadolinium agent used and education of ordering providers.^49,54^ All other studies identified were cohort studies that included index exposures to 3 or more GBCAs. Two of these studies were prospective,^51,60^ and 7 were retrospective.^50,52,55–59^ The retrospective cohort studies were primarily audits of existing patient data in the medical records of a given clinical institution (ie, dialysis unit, health care system). Eight studies included patients with index exposures one of 3 or more GBCAs across ACR groups I and II,^50–52,56–60^ and 1 study included index exposures to ACR groups I and II GBCAs and a GBCA no longer in use (gadofosveset).^55^ Four studies addressing KQ 2 were conducted within the United States,^49,50,54,59^ 1 was conducted in China,^56^ and the rest were conducted within Europe. Of note, 1 study was not designed to assess the risk of NSF after GBCA exposure; instead, incident NSF cases were collected as a secondary outcome.^60^

Across these 12 studies, there were index exposures to all ACR group II GBCAs, with a total of 8,499 patients in ACR group II GBCA index exposures compared with 110,345 patients in the ACR group I index exposures. The most common group II GBCA was gadobenate dimeglumine (7% of index exposures). We found no index exposures to the ACR group III agent gadoexetic acid (ie, gadoxetate disodium). There were 5 exposures to a now-discontinued GBCA, gadofosveset. Diagnosis of NSF was generally established though triangulation of medical record chart reviews or database analyses focusing on ICD codes, documentation of symptoms and exam findings, and sometimes pathology reports from skin biopsies. In addition, some studies surveyed local nephrology and dermatology providers for known NSF cases.^49^ Ten cohort studies reported the diagnostic approach for NSF, which varied and consisted of review of patients’ medical records (n=1); clinical symptoms and examination of skin (n=1); biopsy (n=7); and other clinical criteria (ie, Cowper criteria^61^ [n=1]).^49–52,54–59^ The follow-up of patients in observation for the development of evidence of NSF after index GBCA exposure ranged from 60 days to 10 years with a median of 28 months. Next, we report findings across the 12 included studies grouped by kidney disease status.

### KQ 2A Findings Among All Patients Without Restriction by Kidney Function

Two retrospective cohort studies (1 high and 1 unclear ROB) reviewed the dermatopathology records across all patients at a total of 3 hospitals (2 in the United States^59^ and 1 in China^56^) for NSF or similar histopathologic diagnoses. The US-based study examined the records of 83,121 patients who had received a GBCA-enhanced magnetic resonance imaging (MRI) at 2 large medical centers in New York State: 71,441 gadodiamide (ACR group I), 8,669 gadopentetate dimeglumine (ACR group I), 2,785 gadobenate dimeglumine (ACR group II), and 226 gadoteridol (ACR group II).^59^ That study found 31 NSF cases, of which 15 had received documented high-dose GBCA exposure at 1 of the 2 institutions prior to the development of NSF; the other 16 cases either received GBCA exposures at a different institution or had no available information on GBCA exposure (see Figure 6 for cases by GBCA index exposure across studies). Fourteen of the NSF cases occurred in patients exposed to gadodiamide (ACR group I) and 1 in a patient exposed to gadobenate dimeglumine (ACR group II). That patient developed NSF after 2 exposures to high-dose gadobenate dimeglumine but also had received an unknown GBCA at another medical facility within 60 days of symptom onset. All 15 cases of NSF occurred in patients with impaired renal function at the time of GBCA exposure (3 on chronic dialysis or continuous veno-venous hemofiltration [CVVH] and 12 with eGFR range 5-22 ml/min). This cohort included 131 patients with AKI, which accounted for 11 of the 15 NSF cases (including the case with gadobenate dimeglumine).

The other study examined records in a single military hospital in Beijing, China, and found 0 cases of NSF among 29,315 patient index exposures (28,680 exposed to gadopentetate dimeglumine [ACR group 1] and 635 exposed to gadobenate dimeglumine [ACR group II]) over a 44-month period.^56^ This cohort included 118 patients with CKD or AKI and 33 patients on hemodialysis with GBCA exposure (which agent was not reported). See Table 7 for additional details.

### KQ 2B Findings Among Patients With Key Risk Factors for Chronic Kidney Disease

No studies specifically examined the occurrence of NSF after GBCA exposure among patients with risk factors for CKD. Neither of the 2 cohorts described above that examined NSF occurrence across an entire medical center reported the prevalence of risk factors for CKD among those exposed.

One study with high ROB examined the occurrence of NSF after GBCA exposure among a cohort of 1,167 patients with chronic liver disease (843 patients with eGFR<90 ml/min/1.73m^2^) receiving care at a tertiary liver center.^50^ In this cohort, 186 patients with CKD were exposed to multiple GBCAs, and the index exposure could not be determined. Otherwise, 675 patients received gadobenate dimeglumine (ACR group II), 301 gadoversetamide (ACR group I), and 5 to gadopentetate dimeglumine (ACR group I). There were no cases of NSF reported.

### KQ 2C Findings Among Patients With Any Degree of Kidney Disease

#### Patients With CKD—Any Stage

For this category, we identified 1 cohort study^58^ and 1 case-control study^53^ that included patients exposed to ACR group I and II GBCAs. We found a second cohort study that also included patients exposed to a now-discontinued agent, gadofosveset.^55^ All studies involved retrospective data collection and were found to have a high ROB. The 2 cohort studies mostly consisted of patients with stage 3 CKD or higher (91.9%^58^ and 80.8%^55^). Both had a majority of ACR group II exposures (179^58^ and 1,486^55^) compared with ACR group I exposures (53^58^ and 562^55^). There were only 5 gadofosveset index patient exposures in the one cohort.^55^ Neither cohort study identified any cases of NSF (Figure 6, Table 7). The case-control study included 7 NSF cases with ACR group I index exposure (1 gadopentetate dimeglumine, 6 gadodiamide) and 3 cases with ACR group II index exposures (2 gadobutrol and 1 gadoterate megumine) (Table 8).^53^

#### Patients With CKD—Stages 3 to 5

Two retrospective cohort studies examined GBCA exposures among patients with CKD stage 3 or higher.^49,57^ One study at high ROB compared patients pre- and post-educational and policy changes at an academic medical facility in the United States during which the agent given to patients with eGFR ≤30 was changed from gadodiamide (ACR group I) to gadobenate dimeglumine (ACR group II).^49^ That study found 6 NSF cases among 246 patients with index exposure to gadodiamide and 0 cases among 1,423 patients exposed to gadobenate dimeglumine. The other study was a retrospective cohort at low ROB with 27 patients with stage 3 CKD or higher (median stage 4) who had received GBCA as an alternative contrast agent for conventional angiography (1 exposed to ACR group II agent, 26 exposed to ACR group I agent).^57^ That study found 1 case of NSF in a patient with index exposure to gadodiamide (ACR group I) confounded by 8 additional GBCA exposures (3 of which were with ACR group II agents and 5 were other ACR group I GBCAs).

#### Patients With ESRD Receiving Dialysis

Four studies (2 prospective^51,60^ and 2 retrospective^52,54^) focused specifically on patients receiving dialysis. One study conducted a prospective cohort study (571 patients; unclear ROB) for the French drug regulatory agency among patients on chronic dialysis (both hemodialysis and peritoneal dialysis) for at least 3 months who were scheduled for an MRI with or without GBCA contrast.^51^ Of the 280 patients in this cohort who received an identified GBCA, 6 patients received an ACR group I agent (5 gadopentetate dimeglumine and 1 gadodiamide) and 280 received an ACR group II agent (255 gadoterate meglumine, 12 gadobenate dimeglumine, 11 gadobutrol, and 2 gadoteridol). Patients self-monitored for symptoms of dermatologic changes and were systematically evaluated if symptoms arose. Authors also sought potential cases of NSF and/or dermatologic events from treating nephrologists and regional pharmacovigilance centers. No cases of NSF were identified.

The 2 retrospective studies of patients on chronic dialysis were rated as high ROB. One reported occurrence of NSF before and after a policy-based change in GBCA usage among patients on dialysis (full-dose gadodiamide to half-dose gadobenate dimeglumine) at a large academic institution.^54^ That study found 8 cases of NSF out of 312 patients who received gadodiamide (ACR group I) compared with 0 cases among 784 patients who received gadobenate dimeglumine (ACR group II). The other study reported on 508 hemodialysis patients in Germany, of whom 25 had undergone GBCA exposure (11 ACR group I, 14 ACR group II), and found 0 cases of NSF.^52^

Last, 1 study included a secondary safety analysis at unclear ROB with 38 hemodialysis patients from a prospective parent cardiovascular study in combination with GBCA-exposed patients for clinical reasons.^60^ That study identified 1 confounded case of NSF in a patient with index exposure to an ACR group I agent and a total of 6 GBCA-enhanced MRIs (5 with gadopentetate dimeglumine and 1 with gadobenate dimeglumine).

Figure 6 NSF Occurrence per GBCA Exposure^a^

^*^ Prospective cohort studies.

Abbreviations: ACR=American College of Radiology; CI=confidence interval; CKD=chronic kidney disease; GBCA=gadolinium-based contrast agent; NSF=nephrogenic systemic fibrosis; ROB=risk of bias

Table 7 Cases of NSF After Index Exposure to ACR Group II vs ACR Group I: Cohort

Study | Range Renal Function Included, N Patients Exposed GFR Range/CKD Stage, N Patients Exposed | Index GBCA (ACR Group) | Number of NSF Cases
All Patients Without Restriction by Kidney Function
Prince, 2008^59^ | All = 83,121; eGFR 15-30: 387; eGFR <15: 114 | Gadodiamide (I) = 71,441; Gadopentetate dimeglumine (I) = 8,669; Gadobenate dimeglumine (II) = 2,785; Gadoteridol (II) = 226 | 1 confounded case after gadobenate dimeglumine index exposure vs 14 cases after exposure to gadodiamide
Zou, 2009^56^ | All = 29,315; eGFR 15 to < ~30: 92 | Gadopentetate dimeglumine (I) [Bayer] 17,491 + [Beijing Beilu] 11,189 = 28,680; Gadobenate dimeglumine (II) = 635 | 0
Any Degree of Kidney Disease
Chrysochou, 2010^55^ | Any CKD = 2053; eGFR ≥90: 89; eGFR 60-90: 305; eGFR 45-59/30-44: 918; eGFR 15-30: 491; eGFR <15: 250 | Gadopentetate dimeglumine (I) = 522; Gadodiamide (I) = 40; Gadoterate meglumine (II) = 86; Gadobutrol (II) = 69; Gadobenate dimeglumine (II) = 1331; Gadofosveset trisodium (NA) = 5 | 0
Janus, 2010^58^ | Any CKD = 232 (308 total); eGFR 60-90: 22; eGFR 45-59: 56; eGFR 15-30: 62; eGFR <15: 165 | Gadopentetate dimeglumine (I) 46; Gadodiamide (I) 7; Gadobenate dimeglumine (II) 3; Gadoterate meglumine (II) 176 | 0
Patients With CKD—Stages 3 to 5
Bruce, 2016^49^ | CKD stages 3-5 = 1669 | Gadodiamide (I) 246; Gadobenate dimeglumine (II) 1423 | 6/246 cases gadodiamide vs 0/1423 cases gadobenate dimeglumine
Hoppe, 2010^57^ | CKD stages 3-5 =27 | Gadodiamide (I) 25; Gadopentetate dimeglumine (I) 1; Gadobutrol (II) 1 | 1 confounded NSF case after exposure to gadodiamide, gadoteridol, gadopentetate dimeglumine
Patients With ESRD Receiving Dialysis
Amet, 2014^51^ | ESRD on dialysis = 287 (571 total) | Gadopentetate dimeglumine (I) 5; Gadodiamide (I) 1; Gadoterate meglumine (II) 255; Gadobenate dimeglumine (II) 12; Gadobutrol (II) 11; Gadoteridol (II) 2 | 0
Becker, 2012^52^ | ESRD on dialysis = 25 (508 total) | Gadodiamide (I) 4; Gadopentetate dimeglumine (I) 7; Gadoterate meglumine (II) 5; Gadobutrol (II) 4; Gadoteridol (II) 5 | 0
Martin, 2010^54^ | ESRD dialysis = 1,096 | Gadodiamide (I) 312; Gadobenate dimeglumine (II) 784 | 8/312 gadodiamide vs 0/784 gadobenate dimeglumine
Schieren, 2008^60^ | ESRD on dialysis = 20 (38 total) | Gadopentetate dimeglumine (I) 19; Gadobutrol (II) 1; Gadopentetate /Gadobutrol 18 | 1 gadopentetate dimeglumine
Patients With Chronic Liver Disease
Smorodinsky, 2015^50^ | Chronic liver disease = 981 (1167 total) | Gadopentetate dimeglumine (I) 5; Gadobenate dimeglumine (II) 675; gadoversetamide 301 | 0

Abbreviations: ACR=American College of Radiology; CKD=chronic kidney disease; eGFR=estimated glomerular filtration rate; ESRD=end-stage renal disease; GBCA=gadolinium-based contrast agent; NSF=nephrogenic systemic fibrosis

Table 8 Cases of NSF After Index Exposure to ACR Group II: Case-Control Studies

Study | Range Kidney Function Included, N Patients Exposed GFR Range/CKD Stage, N Patients Exposed | Index GBCA (ACR Group) | Number of NSF Cases
Elmholt, 2011^53^ | Any degree kidney disease = 17 cases NSF (17 controls) | - Mix of agents; - 2 control groups (exposed, unexposed); - 10 cases and controls exposures NR | - 2 cases gadobutrol (1 possibly confounded); - 1 case gadoterate meglumine (1 possibly confounded); - 7 cases group I or unknown

Abbreviations: ACR=American College of Radiology; CKD=chronic kidney disease; GBCA=gadolinium-based contrast agent; GFR=glomerular filtration rate; NSF=nephrogenic systemic fibrosis; NR= not reported

### Summary of NSF Cases from Studies

Across the included studies that examined patients exposed to ACR group II and ACR group I GBCA (188,819 patients), 41 patients were found to have NSF. All but 4 patients had some reported exposure to ACR group I agents (index or otherwise). The degree of renal impairment was not clear across these 4 cases, but all had CKD of some stage and 2 had eGFR <30 or were on dialysis. Of the 4 patients found to have NSF after an index exposure to ACR group II agents, 1 patient had received an unknown GBCA within 2 weeks prior to the index exposure of gadobenate dimeglumine,^59^ 2 received gadobutrol (1 with potential confounding),^53^ and 1 received gadoterate meglumine (also with potential confounding).^53^ Thus, there was one unconfounded case of NSF after index exposure to an ACR group II agents.

### Quality of Evidence for Key Question 2

For the 12 included studies, we found the ROB for occurrence of NSF to be low for 1 study,^57^ unclear for 4 studies,^51,53,59,60^ and high for 7 studies.^49,50,52,54–56,58^ Similar to KQ 1, the most common methodologic issues that led to findings of higher ROB included inadequate or unclear exposure characterization (n=5); inadequate outcome identification (n=9); and higher rates of missing data (n=7). ROB ratings are shown for each study in Figures 7-9.

Figure 7 Risk of Bias Ratings for Included Cohort Studies in KQ 2

Figure 8 Risk of Bias Assessment Across Included Cohort Studies in KQ 2

Figure 9 Risk of Bias Ratings for Included Case-Control Study in KQ 2

### Summary of Findings

Across the 12 studies (1 low ROB, 4 unclear ROB, 7 high ROB), a total of 110,345 patients had index GBCA exposures to ACR group I agents and 8,499 to ACR group II agents. Forty-one cases of NSF were reported with a clearly identified GBCA exposure, of which 37 had a reported exposure to an ACR group I agent and 4 had an index exposure to an ACR group II agent. There were no index exposures to the single ACR group III agent, Gadoexetic acid. Only 1 study included prospective data collection among patients with GBCA exposures,^51^ while the rest assessed GBCA exposure and NSF cases from previously existing chart records and recall of involved providers. While most of the included studies examined occurrence of NSF after index exposure to GBCA among patients with CKD, most of the patient-level GBCA exposures were from the general population studies, which did not restrict enrollment to those with kidney disease. We did not find any studies that focused specifically on patients at risk for CKD, and risk factors for CKD were not reported among patients in cohorts involving undifferentiated general populations.

## Case Reports and Case Series: NSF after Exposure to Newer GBCAs

### Key Point

- We identified 18 cases of NSF after exposure to ACR group II or III GBCAs reported across included case reports and case series; in total 9 cases were unconfounded and occurred after exposure to gadobutrol (n=6) and gadobenate dimeglumine (n=3).

In addition to the above included studies for KQ 1 and KQ 2, we also included case reports and case series of patients diagnosed with NSF after exposure to a newer GBCA (ACR group II or III). While these study designs are generally less rigorous and would not support the determination of the rate of occurrence of NSF after exposure to certain GBCAs, they are described here to provide context for a possible signal of association in the published literature. Table 9 shows aspects of the 18 cases of NSF described in the 10 identified case reports and case series.^62–71^ Nine of the 18 cases were reported to be unconfounded (gadobutrol, n=6; gadobenate dimeglumine, n=3). The other 9 cases included a described confounding with an older GBCA known to be associated with NSF. All but 2 of the cases described reported diagnosis at least in part due to a skin biopsy, though specific diagnostic criteria were generally not reported. Renal function at the time of GBCA exposure was inconsistently reported. We did not conduct a quality assessment of case reports and case series.

Table 9 Case Reports and Case Series of NSF After Index Exposure to Newer GBCAs

Study | Number of NSF Cases | GBCA | Age Gender | Kidney Function^a^ | Diagnostic Criteria/Biopsy | Confounded? | Notes
Endrikat, 2018^62^ | 3 | Gadobutrol | NR | NR | Cowper/Girardi diagnostic (x2) Cowper/Girardi consistent with (x1) | N | Pharmacovigilance database
Lohani, 2017^63^ | 1 | Gadobenate dimeglumine | 57, F | eGFR 64 mL/min/1.73m^2^→ CrCl 22.7mL/min | Skin biopsy | N | Comorbid hypertension; likely inaccurate initial GFR estimation
Barbieri, 2016^64^ | 2 | Multi-agent | 52, F | eGFR 30.3 mL/min/1.73m^2^ | Skin biopsy | Y; Gadodiamide, Gadoteridol^*^, Gadopentetate dimeglumine, Gadobutrol^*^ | Renal transplant; cumulative GBCA dose 1.26mmol/kg (0.68mmol/kg older linear GBCAs)
Barbieri, 2016^64^ | 2 | Multi-agent | 61, F | Unknown | Skin biopsy | Y; Gadodiamide, Gadoteridol, Gadoterate meglumine^*^ | Renal transplant; cumulative GBCA dose 0.81 mmol/kg (0.45mmol/kg older linear GBCAs)
Birka, 2015^65^ | 1 | Multi-agent | 25, F | Dialysis | Skin biopsy | Y; Gadopentetate dimeglumine, Gadoteridol | Renal transplant
Elmholdt, 2013^66^ | 3 (of 64 total) | Gadobutrol (2) Gadobenate dimeglumine (1) | Unknown | Unknown | Skin biopsy | N | Nationwide investigation (Denmark)
Wollanka, 2009^68^ | 1 | Gadobutrol | 69, M | Dialysis | Skin biopsy | N | Hyperphosphatemia, anemia, arteriosclerosis
Shin, 2008^69^ | 1 | Multi-agent | 60, F | eGFR ~30ml/min/1.73m^2^ | Skin biopsy | Y; Gadobenate dimeglumine (105ml total); gadopentetate dimeglumine dimeglumine (60ml total) | Hypertension, diabetes mellitus, coronary artery disease
Sadowski, 2007^70^ | 1 (of 13 total) | Multi-agent | Unknown, F | eGFR 21.6-23.9 ml/min/1.73m^2^ | Skin biopsy | Y; Gadodiamide; Gadobenate dimeglumine | Liver transplant, angiosarcoma, portal vein thrombosis
Semelka, 2016^71^ | 3 (of 4 total) | Multi-agent | 43, F | “Normal renal function” | “Subcutaneous lesions, skin tightness, and shiny appearance of skin over fingers” | Y; Gadoversetamide; gadoexetic acid; gadobutrol | Exam 3.5 months after GBCA exposure; h/o Guillain-Barre syndrome
Semelka, 2016^71^ | 3 (of 4 total) | Gadobenate dimeglumine | 58, F | “Normal renal function” | Skin biopsy | Gadobenate dimeglumine | Exam 7 years after GBCA exposure
Semelka, 2016^71^ | 3 (of 4 total) | Multi-agent | 55, F | “Normal renal function” | “Skin and subcutaneous tissues of her hands and feet were thickened and red with a doughy consistency” | Gadodiamide; Gadobenate dimeglumine | Exam 8 years after GBCA exposure
Becker, 2010^67^ | 2 (of 23 total) | Multi-agent | Unknown | Unknown | Skin biopsy | Y; Gadobutrol; Gadopentetate dimeglumine | German registry
Becker, 2010^67^ | 2 (of 23 total) | Multi-agent | Unknown | Unknown | Skin biopsy | Y; Gadoterate meglumine; unspecified older linear | German registry

a At time of GBCA exposure.

* Most proximal to diagnosis of NSF.

Abbreviations: eGFR=estimated glomerular filtration rate; F=female; GBCA=gadolinium-based contrast agent; M=male; N=no; Y=yes