# APPENDIX H Glossary

For full study citations in this appendix, please refer to the report’s main reference list.

Term: Definition
Certainty of evidence (COE): We assessed COE using the Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach^32^ for 4 domains:
  Domain | Rating | How Assessed
  Risk of bias | Low; Unclear; High | Assessed primarily through study design and aggregate study quality
  Consistency | Not serious inconsistency; Serious inconsistency; Very serious inconsistency | Assessed primarily through whether effect sizes are generally on the same side of “no effect,” the overall range of effect sizes, and statistical measures of heterogeneity
  Directness | Not indirect; Serious indirectness; Very serious indirectness | Assessed by whether the evidence involves direct comparisons or indirect comparisons through use of surrogate outcomes or use of separate bodies of evidence
  Precision | Not serious imprecision; Serious imprecision; Very serious imprecision | Based primarily on the size of the confidence intervals of effect estimates, the optimal information size and considerations of whether the confidence interval crossed a clinical decision threshold
  Summary COE ratings for a body of evidence:
  - High—High confidence that the true effect lies close to that of the estimate of the effect.
  - Moderate—Moderate confidence in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
  - Low—Limited confidence in the effect estimate. The true effect may be substantially different from the estimate of the effect.
  - Very low—Very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.
  - Insufficient—Impossible or imprudent to rate. In these situations, a rating of insufficient is assigned.
Chronic kidney disease stages: - Stage 1 with normal or high estimated glomerular filtration rate (eGFR): eGFR >90 mL/min
  - Stage 2 Mild CKD: eGFR = 60-89 mL/min
  - Stage 3A Moderate CKD: eGFR = 45-59 mL/min
  - Stage 3B Moderate CKD: eGFR = 30-44 mL/min
  - Stage 4 Severe CKD: eGFR = 15-29 mL/min
  - Stage 5 End-Stage CKD: eGFR <15 mL/min
Index exposure: The only gadolinium contrast agent exposure as reported by the study, or the primary exposure for studies in which patients were exposed to multiple gadolinium-based contrast agents (ie, confounded exposures).
Objective outcomes (ie, non–patient-reported outcomes): Outcomes that are not subject to a large degree of individual interpretation and are likely to be reliably measured across patients in a study, by different health care providers, and over time.
Patient-reported outcomes: Outcomes that are directly reported by the patient without interpretation of the patient’s response by a clinician or anyone else and pertains to the patient’s health, quality of life, or functional status associated with health care or treatment.
Risk of bias (ROB): An assessment of study quality. In this report, we used the Cochrane EPOC ROB tool, which is applicable to randomized and nonrandomized studies^29^:
  - Randomization and allocation concealment
  - Comparability of groups at baseline
  - Blinded outcomes assessment
  - Completeness of follow-up and differential loss to follow-up
  - Whether incomplete data were addressed appropriately
  - Protection against contamination
  - Selective outcomes reporting
  - Intervention independent from other changes (specific to interrupted time series)
  - Intervention pre-specified (specific to interrupted time series)
  - Intervention affect on data collection (specific to interrupted time series)
  Summary ROB ratings for a study:
  - Low ROB—Bias, if present, is unlikely to alter the results seriously
  - Unclear ROB—Bias that raises some doubts about the results
  - High ROB—Bias that may alter the results seriously
  For observational cohort and case-control studies, we adapted the Newcastle-Ottawa ROB scale (from the version modified by Guyatt and colleagues). For documentation and tools, refer to Evidence Partners’ Methodological Resources at https://www.evidencepartners.com/resources/methodological-resources/.