# APPENDIX G Study Characteristics

For full study citations in this appendix, please refer to the report’s main reference list.

Study Country (Companion Study) | N Patients GBCA-Exposed (Total Study N) | GBCA (N) | Study Period | GFR Range/CKD | NSF Diagnostic Criteria | Follow-up | Risk of Bias
Nonrandomized controlled trial (KQ 1)
Deray, 2013^48^; Belgium, France, Italy, Spain | 70 (70) | Gadoterate meglumine (70) | 2008-2011 | CKD stages 3-5 | NR | 3 months | High; Pharmaceutical affiliated
Case-control study (KQ 2)
Elmholdt, 2011^53^; Denmark; (Elmholdt, 2010^83^) | 565 (4648) | Gadobutrol (2) Gadoteric acid (8) | 1997-2009 | Any CKD | NR | NR; mean time from NSF symptom onset to time of diagnosing NSF was 5 ± 3 years (range 0-11) | Unclear
Cohort studies (single agent, KQ 1)
Abujedeh, 2009^46^; USA | 92 (250) | Gadobenate dimeglumine (250) | 2007-2008 | CKD stages 3-5 | Non-biopsy: skin exams were done on 183 patients | Mean 108 ± 60 days (range 3-253 days) | Unclear
Bryant, 2009^33^; USA (California) | 148 (168) | Gadobenate dimeglumine (168) | 2007-2008 | CKD stages 3-5 | Biopsy; specific criteria not specified | 6 months | Unclear
de Campos, 2011^45^; USA (North Carolina) | 2 (69) | Gadobenate dimeglumine (25 quarter-dose; 44 half-dose) | 2009-2010 | CKD stages 3-5 | NR | Mean 8 months (range 4-12 months) | High
Gheuens, 2014^34^; Belgium | 10 (10) | Gadoteric acid (10) | 2011-2012 | Dialysis | NR | Up to 3 months | High; Pharmaceutical affiliated
Lauenstein, 2015^35^; Multinational | 186 (357) | Gadoexetate disodium (357) | 2009-2013 | Any CKD | Girardi criteria | Up to 24 months patients with mild renal impairment were not included in follow-up | High; Pharmaceutical affiliated
McKinney, 2015^42^; USA (Minnesota) | 31 (31) | Gadoxetate disodium (31) | 2011-2014 | CKD stages 3-5 | NR | Mean 13.2 months, SD 11.5 (range 1.1-43 months) | High
Michaely, 2017^36^; Germany [18 centers], Italy [10], Spain [3], Austria [6], Switzerland [1], Canada [5], Australia [2], South Korea [8], and Thailand [2] | 908 (927) | Gadobutrol (908) | 2008-2015 | Any CKD | Girardi criteria | 24 months; patients with mild renal impairment were not included in the follow-up | Unclear; Pharmaceutical affiliated
Nandwana, 2015^43^; USA (Georgia) | 401 (401) | Gadobenate dimeglumine (401) | 1/2010-12/2010 | Dialysis | Patient’s electronic medical record | Mean 2.35 years ± 1.61, (range 0-4.61) | Unclear
Prince, 2017^37^; China, Kazakhstan, Kyrgyzstan, Korea, Taiwan, Thailand, Bosnia, Herzegovina, Czech Republic, France, Germany, Greece, Hungary, Italy, Russia, Spain, Canada, South Africa; (Glutig, 2016^84^) | 23,708 (23,708) | Gadobutrol (23708) | 2010-2013 | All | NR | Up to 3 months | High; Pharmaceutical affiliated
Reilly, 2008^47^; USA (Texas) | 141 (141) | Gadoteridol (141) | 2000-2007 | Dialysis | NR | Mean 570 days (SD 474) | High
Shaffer, 2015^44^; USA (Georgia) | 352 (352) | Gadobenate dimeglumine (352) | 2007-2013 | Chronic liver disease | Examination of the patient medical record | Median 17 months (IQR 41.0) | High
Soulez, 2015^38^; USA, Canada, Europe | 534 (947) | Gadobenate dimeglumine (329); Gadoteridol (160) | 2008-2013 | CKD stages 3-5 | Girardi criteria | 2 years | High; Pharmaceutical affiliated
Soyer, 2017^39^; Argentina, Austria, China, France, Germany, India, Italy, Saudi Arabia, Spain, UK | 35499 (35499) | Gadoterate meglumine (35499) | 2008-2013 | All | NR | Mean 148 days, (range 3 months to 996 days) followed up only patients with impaired renal function | Low; Pharmaceutical affiliated
Tsushima, 2018^40^; Japan | 3337 (3337) | Gadobutrol (3337) | 2015-2017 | All | NR | 3-25 months in patients with eGFR <30 | Unclear; Pharmaceutical affiliated
Young, 2018^41^; Scotland | 15,377 (22,468) | Gadoterate meglumine (22,325 adults; 572 pediatric) | 2004-2016 | Any CKD | Diagnosis determined only via dermatology records | Mean 6.0 years ± 2.5 (range 8 months-15 years) (adults); 6.2 years ± 2.4 (1-10 years) (pediatrics) | Unclear
Cohort studies (multiple agents, KQ 2)
Amet, 2014^51^; France | (n=571) | Gadoteric acid (255); Gadobenate (12); Gadobutrol (11); Gadopentetate (5); Gadoteridol (2); Gadodiamide (1) | 2009-2011 | Dialysis | Biopsy; criteria; NR | At least 4 months | Unclear
Becker, 2012^52^; Germany | 25 (508) | Gadodiamide (4); Gadopentetate (7); Gadoterate (5); Gadobutrol (4); Gadoteridol (5) | 2006-2010 | Dialysis | Biopsy; criteria; NR | 4 years | High
Bruce, 2016^49^; USA (Wisconsin) | 1669 (1669) | Gadobenate dimeglumine (1423); Gadodiamide (246) | | CKD stages 3-5 | Clinical symptoms + deep skin biopsy | Not defined; up to 9 years for gadodiamide earlier cohort | High
Chrysochou, 2010^55^; UK | 2053 (2053) | Gadopentetate (572); Gadoterate (86); Gadodiamide (40); Gadobutrol (69); Vasovist (5); Gadobenate (1321) | 2000-2009 | Any CKD | Includes biopsy findings, reasons for derm/rheum referral as outcomes | Mean 28.6 ± 18.2 months | High
Hoppe, 2010^57^; Switzerland | 27 (27) | Gadodiamide (25); Gadopentetate (1); Gadobutrol (1) | 2000-2002 | CKD stages 3-5 | Biopsy, dermatology reports | Mean 28 months (± 29.5); range 1-84 months | Low
Janus, 2010^58^; France | 232 (308) | Gadoterate (176); Gadopentetate (46); Gadodiamide (7); Gadobenate (3) | 2005-2006 | Any CKD | Non-biopsy; clinician diagnosis | 4 months | High
Martin, 2010^54^; USA (Georgia) | 1096 (1096) | Gadobenate dimeglumine (784); Gadodiamide (312) | 10/2003 - 1/2007 | Dialysis | Biopsy; criteria; NR | 6 months or more | High
Prince, 2008^59^; USA (New York) | 82,804 (83,121) | Gadodiamide (71441); Gadopentetate (8669); Gadobenate (2785); Gadoteridol (226) | 1997-2007 | All | Biopsy; criteria; NR | Unclear; 10 year retrospective study | Unclear
Schieren, 2008^60^; Germany | 20 (38) | Gadopentetate (37); confounded with Gadobutrol (25) | 2003-2005 | Dialysis | Unclear “clinical follow-up” | 1 year | Unclear
Smorodinsky, 2015^50^; USA (California) | 981 (1,167) | Gadobenate (675); Gadoversetamide (301); Gadopentetate (5); Confounded (186) | 2004-2007 | Chronic liver disease | As per chart in dermatopath records, chart notes, discharge summaries or ICD-9 codes | At least 60 days; mean 1505 days (range 61-3400) | High
Zou, 2009^56^; China | 29,315 (29,315) | Gadopentetate [Bayer] (17,491) + [Beijing Beilu] (11,189); Gadobenate (635) | 2005-2008 | All | Non-biopsy | 3 months | High

Abbreviations: CKD=chronic kidney disease; GBCA=gadolinium-based contrast agent; GFR=glomerular filtration rate; NR=not reported; NSF=nephrogenic systemic fibrosis