# APPENDIX F Peer Review Comments and Response Table

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 5 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No | Acknowledged
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | No | Acknowledged
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Include narrative or table of FDA post marketing reports on NSF associated with GBCA that may not have been published | This is an excellent suggestion, and we have made the addition as Appendix A.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Overall excellent review.; Below *xxxxx* is used to indicate suggested additions or changes. | Thank you, we have made the suggested changes and added clarifications in the final report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Page 4, line 22. Please clarify if all patients reported in KQ2 studies had exposure to both Group 1 and Group 2 agents, or if some or most patients had exposure to just one or the other.; Page 6, line 50. “… patients with *advanced* renal insufficiency.”; Page 8, line 23. As a diagnostic tool *and depending on clinical indication*, … | A sentence has been added to the Executive Summary under the KQ2 Results section to clarify exposures to Group I and Group II.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Page 15, line 11. Definition of ‘index GBCA exposure’ is somewhat buried here. Recommend including this definition in Executive Summary section.; Page 53—59. Use of periods in table bullet points is inconsistent.; Page 55, line 20. Correct spacing between serum and creatinine.; Page 55, line 26 (and others). Remove footnote indicators if footnotes not included in table.; Page 56, line 31. HD should be performed *following* GBCA administration, ideally within 2—3 hours… [The actual guidelines say “the same day as,” however ‘following’ is a clearer restatement of the intent.]; Page 59, line 21. *Do* not use…; Page 59, line 34. *Do*not use… | A sentence has been added to the Executive Summary under the Data Synthesis and Analysis section to clarify index exposure.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | Please review terminology used to describe chronic kidney disease throughout document. In accordance with current accepted terminology, Acute renal insufficiency should be changed to Acute Kidney Injury; chronic renal insufficiency should be changed to chronic kidney disease. | Thank you, we have made these changes in the final report.