# APPENDIX D Excluded Studies

Excluded references are listed following this table.

| Exclusion Reason
Study | Not full publication | Not population of interest | Not eligible intervention | Not eligible design | Not eligible outcome
Abujudeh, 2010^1^ | | | | | X
Aggarwal, 2011^2^ | | | X
Aires, 2007^3^ | | | X
Al Habeeb, 2009^4^ | | | X
Alhadad, 2012^5^ | | | X
Altun, 2009^6^ | | | X
Aluma, 2007^7^ | | | X
Amuluru, 2009^8^ | | | X
Anavekar, 2008^9^ | | | X
Andrews, 2008^10^ | X
Anonymous, 2007^11^ | X
Anonymous, 2010^12^ | X
Anonymous, 2010^13^ | X
Anzalone, 2011^14^ | X
Auron, 2006^15^ | | | X
Azzouz, 2014^16^ | | | X
Bahrami, 2009^17^ | | | X
Bainotti, 2008^18^ | | | X
Bangsgaard, 2011^19^ | | | X
Bangsgaard, 2009^20^ | | | X
Barker-Griffith, 2011^21^ | | | X
Baron, 2003^22^ | | | X
Baumgarten, 2008^23^ | X
Bayliss, 2008^24^ | | | X
Bernstein, 2014^25^ | | | X
Bhaskaran, 2010^26^ | | | X
Blankholm, 2013^27^ | | | X
Bridges, 2009^28^ | | | X
Broome, 2007^29^ | | | X
Burke, 2016^30^ | | | | | X
Cassis, 2006^31^ | | | X
Chan, 2009^32^ | | | X
Chandran, 2009^33^ | | | X
Chao, 2008^34^ | | | X
Chen, 2009^35^ | | | X
Cheng, 2007^36^ | | | X
Chiu, 2004^37^ | | | X
Choi, 2011^38^ | X
Chow, 2011^39^ | | | X
Christensen, 2011^40^ | | | X
Chung, 2004^41^ | | | X
Clorius, 2007^42^ | | | X
Collidge, 2007^43^ | | | X
Cowper, 2006^44^ | X
Cowper, 2000^45^ | | | X
Craig, 2011^46^ | | | X
Cubero-Gomez, 2017^47^ | | | | | X
Cuende, 2009^48^ | | | X
Cuffy, 2011^49^ | | | X
Daram, 2005^50^ | | | X
Dawn, 2004^51^ | | | X
de Kerviler, 2016^52^ | | | | X
Deng, 2010^53^ | | | X
Deng, 2008^54^ | | | X
Deo, 2007^55^ | | | X
Dewan, 2016^56^ | | | X
Dhungel, 2008^57^ | X
Do, 2012^58^ | | | X
Duffy, 2008^59^ | | | X
Dundova, 2005^60^ | | | X
Dupont, 2005^61^ | | | X
Edgar, 2010^62^ | | | X
Edsall, 2004^63^ | | | X
Edward, 2010^64^ | | | X
Elmholdt, 2010^65^ | | | | X
Endrikat, 2015^66^ | | | | | X
Endrikat, 2016^67^ | | | | X
Evenepoel, 2004^68^ | | | X
Ferner, 2011^69^ | | | | X
Fingerhut, 2018^70^ | | | X
Firoz, 2008^71^ | | | X
Foss, 2009^72^ | | | X
Friedman, 2012^73^ | | | | X
Fuah, 2017^74^ | | | X
Gambichler, 2004^75^ | | | X
George, 2006^76^ | | | X
Gharacholou, 2011^77^ | | | X
Gibson, 2006^78^ | | | X
Giersig, 2007^79^ | X
Gilliet, 2005^80^ | | | X
Glaich, 2005^81^ | | | X
Goddard, 2007^82^ | | | X
Granata, 2016^83^ | | | | | X
Grand, 2012^84^ | | | X
Grebe, 2008^85^ | | | X
Grobner, 2006^86^ | | | X
Gulati, 2008^87^ | | | X
Gutierrez, 2012^88^ | | | | X
Gutierrez, 2015^89^ | | | | | X
Gutierrez, 2015^90^ | | | | | X
Hall, 2012^91^ | | | | X
Haller, 2011^92^ | X
Halteh, 2017^93^ | | | X
Hamilton, 2011^94^ | | | | | X
Hanna, 2014^95^ | | | X
Hashemi, 2013^96^ | | | X
Hauser, 2004^97^ | | | X
He, 2016^98^ | | | X
Hedley, 2007^99^ | X
Hedley, 2007^100^ | X
Heinz-Peer, 2010^101^ | | | X
Hickson, 2010^102^ | | | X
Hidalgo Parra, 2008^103^ | | | X
High, 2007^104^ | | | X
High, 2007^105^ | | | X
Hodnett, 2011^106^ | | | X
Homayoon, 2014^107^ | | | | | X
Hong, 2011^108^ | X
Hope, 2009^109^ | | | X
Hubbard, 2003^110^ | | | X
Hurley, 2012^111^ | | | | | X
Introcaso, 2008^112^ | | | X
Introcaso, 2007^113^ | | | X
Ishiguchi, 2010^114^ | | | | | X
Jalandhara, 2011^115^ | | | | X
Jan, 2008^116^ | X
Jan, 2003^117^ | | | X
Jikki, 2008^118^ | X
Kafi, 2004^119^ | | | X
Kalisz, 2011^120^ | | | X
Kanda, 2015^121^ | | | | | X
Kartono, 2011^122^ | | | X
Kaul, 2012^123^ | | | | X
Kay, 2008^124^ | | | X
Kay, 2008^125^ | | | X
Kelly, 2008^126^ | | | X
Kendrick-Jones, 2011^127^ | | | X
Kennedy, 2010^128^ | | | X
Khor, 2013^129^ | X
Khurana, 2008^130^ | | | X
Khurram, 2007^131^ | | | X
Kim, 2006^132^ | | | X
Kitaura, 2010^133^ | | | X
Knapp, 2010^134^ | | | X
Koratala, 2017^135^ | | | X
Koreishi, 2009^136^ | | | X
Kraetschmer, 2009^137^ | X
Kramer, 2011^138^ | | | | | X
Kreuter, 2008^139^ | | | X
Krishnamurthy, 2011^140^ | | | | X
Kroshinsky, 2009^141^ | | | X
Krous, 2007^142^ | | | X
Kucher, 2006^143^ | | | X
Kunst, 2011^144^ | | | | X
Larson, 2015^145^ | | | X
Lauenstein, 2007^146^ | | | X
Learned, 2013^147^ | | | X
LeBoit, 2003^148^ | X
Lee, 2009^149^ | | | | X
Lee, 2012^150^ | | | | X
Leiner, 2009^151^ | X
Lemy, 2010^152^ | | | X
Leung, 2009^153^ | | | X
Levine, 2004^154^ | | | X
Lewis, 2006^155^ | | | X
Lim, 2007^156^ | | | X
Lu, 2009^157^ | | | X
Mackay-Wiggan, 2003^158^ | | | X
Marckmann, 2008^159^ | | | X
Markus, 2005^160^ | | | X
Martin, 2008^161^ | X
Martin, 2018^162^ | | | | | X
Mathur, 2008^163^ | | | X
Matich, 2014^164^ | X
Matsumoto, 2012^165^ | | | X
Mavrogeni, 2011^166^ | | | | X
Mazhar, 2009^167^ | | | X
McNeill, 2002^168^ | | | X
Mendoza, 2006^169^ | | | X
Mihai, 2011^170^ | | | | X
Miyamoto, 2011^171^ | | | X
Mohidin, 2018^172^ | | | X
Morcos, 2011^173^ | | X
Moreno-Romero, 2007^174^ | | | X
Moschella, 2004^175^ | | | X
Murata, 2016^176^ | | | | | X
Nakai, 2009^177^ | | | X
Nardone, 2014^178^ | | | X
Nazarian, 2011^179^ | | | X
Nguyen, 2014^180^ | | | X
Nielsen, 2010^181^ | X
Obermoser, 2004^182^ | | | X
Okada, 2001^183^ | | | X
Ota, 2012^184^ | X
Othersen, 2007^185^ | | | X
Pagel, 2011^186^ | | | | X
Panda, 2006^187^ | | | X
Panesar, 2008^188^ | | | X
Pao, 2009^189^ | | | X
Penfield, 2008^190^ | X
Perazella, 2007^191^ | | | | X
Perazella, 2003^192^ | | | X
Perazella, 2007^193^ | | | X
Perez-Rodriguez, 2009^194^ | | | X
Pieringer, 2008^195^ | X
Prince, 2011^196^ | | | | | X
Pryor, 2007^197^ | | | X
Radbruch, 2015^198^ | | | | | X
Ray, 2016^199^ | | | X
Riccabona, 2008^200^ | X
Roberts, 2016^201^ | | | | X
Robinson, 2011^202^ | X
Rodby, 2011^203^ | X
Ross, 2015^204^ | | | X
Ruiz-Genao, 2005^205^ | | | X
Rydahl, 2008^206^ | | | X
Saenz, 2006^207^ | | | X
Sambol, 2011^208^ | | | X
Sanchez-Ross, 2007^209^ | | | X
Sanyal, 2011^210^ | | | X
Saussereau, 2008^211^ | | | X
Schieren, 2009^212^ | | | X
Schietinger, 2008^213^ | | | X
Schleichert, 2012^214^ | | | X
Schmiedl, 2009^215^ | | | X
Schmook, 2005^216^ | | | X
Schneider, 2007^217^ | | | | | X
Schroeder, 2008^218^ | | | X
Sego, 2008^219^ | | | X
Semelka, 2016^220^ | | | | X
Shabana, 2008^221^ | | | X
Shah, 2017^222^ | | | | X
Sharfuddin, 2011^223^ | | | X
Sharma, 2008^224^ | | | X
Shimoji, 2012^225^ | | | X
Singh, 2008^226^ | | | X
So, 2009^227^ | | | X
Solomon, 2007^228^ | | | X
Soulez, 2008^229^ | | | | | X
Steen, 2009^230^ | | | X
Streams, 2003^231^ | | | X
Su, 2009^232^ | | | X
Su, 2009^233^ | | | X
Swaminathan, 2008^234^ | | | X
Tan, 2004^235^ | | | X
Tanaka, 2016^236^ | | | | | X
Thakral, 2009^237^ | | | X
Thakral, 2007^238^ | | | X
Thomsen, 2006^239^ | X
Thomsen, 2008^240^ | X
Thomsen, 2010^241^ | | | | X
Thomsen, 2006^242^ | X
Thomson, 2015^243^ | | | X
Thurnher, 2007^244^ | | | | X
Ting, 2003^245^ | | | X
Todd, 2007^246^ | | | X
Tsai, 2007^247^ | | | X
Tsushima, 2008^248^ | X
Ustuner, 2011^249^ | | | X
Valsangiacomo Buechel, 2011^250^ | | | | X
Voth, 2011^251^ | | | | | X
Wahba, 2007^252^ | | | X
Wang, 2011^253^ | | | X
Weigle, 2008^254^ | | | X
Weiss, 2007^255^ | | | X
Weller, 2014^256^ | | | | X
Wertman, 2008^257^ | | | X
Wiginton, 2008^258^ | | | X
Wilford, 2010^259^ | | | X
Wilson, 2017^260^ | | | X
Winship, 2013^261^ | | | X
Woodard, 2012^262^ | | | | | X
Yerram, 2007^263^ | | | X
Yoldez, 2018^264^ | X
Zelasko, 2008^265^ | | | X
Zhang, 2015^266^ | | | | X
Zhang, 2017^267^ | | | X
Zou, 2011^268^ | | | | X

## References to Appendix D

1 Abujudeh HH, Kosaraju VK, Kaewlai R. Acute adverse reactions to gadopentetate dimeglumine and gadobenate dimeglumine: experience with 32,659 injections. AJR Am J Roentgenol. 2010;194(2):430–4.20093606
2 Aggarwal A, Froehlich AA, Essah P, . Complications of nephrogenic systemic fibrosis following repeated exposure to gadolinium in a man with hypothyroidism: a case report. J Med Case Rep. 2011;5:566.22152227
3 Aires NB, Sotto MN, Nico MM. Nephrogenic fibrosing dermopathy: report of two cases. Acta Derm Venereol. 2007;87(6):521–4.17989891
4 Al Habeeb A, Partington S, Rosenthal D, . Skin thickening in a hemodialysis patient: a case of nephrogenic fibrosing dermopathy. J Cutan Med Surg. 2009;13(2):110–4.19298781
5 Alhadad A, Sterner G, Svensson A, . Incidence of nephrogenic systemic fibrosis at a large university hospital in Sweden. Scand J Urol Nephrol. 2012;46(1):48–53.22008005
6 Altun E, Martin DR, Wertman R, . Nephrogenic systemic fibrosis: change in incidence following a switch in gadolinium agents and adoption of a gadolinium policy--report from two U.S. universities. Radiology. 2009;253(3):689–96.19789233
7 Aluma MS, Restrepo R, Gaviria M. Nephrogenic fibrosing dermopathy: first Colombian case. Dermatol Online J. 2007;13(3):24.
8 Amuluru L, High W, Hiatt KM, . Metal deposition in calcific uremic arteriolopathy. J Am Acad Dermatol. 2009;61(1):73–9.19406504
9 Anavekar NS, Chong AH, Norris R, . Nephrogenic systemic fibrosis in a gadolinium-naive renal transplant recipient. Australas J Dermatol. 2008;49(1):44–7.18186849
10 Andrews MJ. Nephrogenic systemic fibrosis: MRI hazards in patients with severe renal impairment. Journal of the Royal College of Physicians of Edinburgh. 2008;38(3):230–231.
11 Factors that might affect risk of gadodiamide-related nephrogenic systemic fibrosis. Nature Clinical Practice Nephrology. 2007;3(8):411.
12 First reports of serious adverse drug reactions in recent weeks. Drugs and Therapy Perspectives. 2010;26(3):22–23.
13 Forum. Pharmaceutical Medicine. 2010;24(4):239–253.
14 Anzalone N. Defining contrast: Latest data on the safety of gadobutrol-enhanced MRI and efficacy in CNS applications. Vol. 17; 2011:31–34.
15 Auron A, Shao L, Warady BA. Nephrogenic fibrosing dermopathy in children. Pediatr Nephrol. 2006;21(9):1307–11.16821025
16 Azzouz M, Rømsing J, Thomsen HS. Can a structured questionnaire identify patients with reduced renal function? Eur Radiol. 2014;24(3):780–784.24275804
17 Bahrami S, Raman SS, Sauk S, . Ten-year experience with nephrogenic systemic fibrosis: case-control analysis of risk factors. J Comput Assist Tomogr. 2009;33(6):819–23.19940643
18 Bainotti S, Rota E, Bertrero M, . Nephrogenic systemic fibrosis: the first Italian gadolinium-proven case. Clin Nephrol. 2008;70(6):514–7.19049709
19 Bangsgaard N, Hansen JM, Marckmann P, . Nephrogenic systemic fibrosis symptoms alleviated by renal transplantation. Dialysis and Transplantation. 2011;40(2):86–87.
20 Bangsgaard N, Marckmann P, Rossen K, . Nephrogenic systemic fibrosis: late skin manifestations. Arch Dermatol. 2009;145(2):183–7.19221265
21 Barker-Griffith A, Goldberg J, Abraham JL. Ocular pathologic features and gadolinium deposition in nephrogenic systemic fibrosis. Arch Ophthalmol. 2011;129(5):661–3.21555622
22 Baron PW, Cantos K, Hillebrand DJ, . Nephrogenic fibrosing dermopathy after liver transplantation successfully treated with plasmapheresis. Am J Dermatopathol. 2003;25(3):204–9.12775982
23 Baumgarten M, Gehr T, Mirovski MAX. Progressive skin fibrosis. Am Fam Physician. 2008;78(4):505–508.18756661
24 Bayliss G, Jacobs W, Williams M. Renal failure and abdominal pain as the presenting symptoms of a rare tumor of the aorta masquerading as a calcified plaque. NDT Plus. 2008;1(5):316–8.25983922
25 Bernstein EJ, Isakova T, Sullivan ME, . Nephrogenic systemic fibrosis is associated with hypophosphataemia: a case-control study. Rheumatology (Oxford). 2014;53(9):1613–7.24706993
26 Bhaskaran A, Kashyap P, Kelly B, . Nephrogenic systemic fibrosis following acute kidney injury and exposure to gadolinium. Indian J Med Sci. 2010;64(1):33–6.22301807
27 Blankholm AD, Ginnerup-Pedersen B, Stausbøl-Grøn B, . Non-contrast enhanced magnetic resonance angiography techniques in candidates for kidney transplantation: A comparative study. Radiography. 2013;19(3):212–217.
28 Bridges MD, St Amant BS, McNeil RB, . High-dose gadodiamide for catheter angiography and CT in patients with varying degrees of renal insufficiency: Prevalence of subsequent nephrogenic systemic fibrosis and decline in renal function. AJR Am J Roentgenol. 2009;192(6):1538–43.19457816
29 Broome DR, Cottrell AC, Kanal E. Response to “Will dialysis prevent the development of nephrogenic systemic fibrosis after gadolinium-based contrast administration?”. AJR Am J Roentgenol. 2007;189(4):W234–5.17885040
30 Burke LM, Ramalho M, AlObaidy M, . Self-reported gadolinium toxicity: A survey of patients with chronic symptoms. Magn Reson Imaging. 2016;34(8):1078–80.27211256
31 Cassis TB, Jackson JM, Sonnier GB, . Nephrogenic fibrosing dermopathy in a patient with acute renal failure never requiring dialysis. Int J Dermatol. 2006;45(1):56–9.16426379
32 Chan KH, Tang WY, Hau KC, . Nephrogenic systemic fibrosis in a Chinese renal-transplant recipient. Clin Exp Dermatol. 2009;34(2):244–6.19120400
33 Chandran S, Petersen J, Jacobs C, . Imatinib in the treatment of nephrogenic systemic fibrosis. Am J Kidney Dis. 2009;53(1):129–32.19012999
34 Chao CC, Yang CC, Hsiao CH, . Nephrogenic systemic fibrosis associated with gadolinium use. J Formos Med Assoc. 2008;107(3):270–4.18400614
35 Chen W, Huang SL, Huang CS, . Nephrogenic systemic fibrosis in advanced chronic kidney disease: a single hospital’s experience in Taiwan. Eur J Dermatol. 2009;19(1):44–9.19059824
36 Cheng S, Abramova L, Saab G, . Nephrogenic fibrosing dermopathy associated with exposure to gadolinium-containing contrast agents - St. Louis, Missouri, 2002-2006. Vol. 297; 2007.
37 Chiu H, Wells G, Carag H, . Nephrogenic fibrosing dermopathy: a rare entity in patients awaiting liver transplantation. Liver Transpl. 2004;10(3):465–6.15004779
38 Choi JA, Gold GE. MR imaging of articular cartilage physiology. Magn Reson Imaging Clin N Am. 2011;19(2):249–282.21665090
39 Chow DS, Bahrami S, Raman SS, . Risk of nephrogenic systemic fibrosis in liver transplantation patients. AJR Am J Roentgenol. 2011;197(3):658–62.21862808
40 Christensen KN, Lee CU, Hanley MM, . Quantification of gadolinium in fresh skin and serum samples from patients with nephrogenic systemic fibrosis. J Am Acad Dermatol. 2011;64(1):91–6.21036418
41 Chung HJ, Chung KY. Nephrogenic fibrosing dermopathy: response to high-dose intravenous immunoglobulin. Br J Dermatol. 2004;150(3):596–7.15030351
42 Clorius S, Technau K, Watter T, . Nephrogenic systemic fibrosis following exposure to gadolinium-containing contrast agent. Clin Nephrol. 2007;68(4):249–52.17969494
43 Collidge TA, Thomson PC, Mark PB, . Gadolinium-enhanced MR imaging and nephrogenic systemic fibrosis: retrospective study of a renal replacement therapy cohort. Radiology. 2007;245(1):168–75.17704357
44 Cowper SE, Bucala R, Leboit PE. Nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis-setting the record straight. Semin Arthritis Rheum. 2006;35(4):208–10.16461067
45 Cowper SE, Robin HS, Steinberg SM, . Scleromyxoedema-like cutaneous diseases in renal-dialysis patients. Lancet. 2000;356(9234):1000–1.11041404
46 Craig AJ, Britten A, Heenan SD, . Significant differences when using MDRD for GFR estimation compared to radionuclide measured clearance. Eur Radiol. 2011;21(10):2211–7.21603880
47 Cubero-Gomez JM, Guerrero Marquez FJ, Diaz-de la-Llera L, . Severe thrombocytopenia induced by iodinated contrast after coronary angiography: The use of gadolinium contrast and intravascular ultrasound as an alternative to guide percutaneous coronary intervention. Rev Port Cardiol. 2017;36(1):61.e1–61.e4.27986390
48 Cuende E, Aldamiz M, Portu J, . Nephrogenic systemic fibrosis in a patient with a p-ANCA systemic vasculitis. Reumatol Clin. 2009;5(6):264–7.21794627
49 Cuffy MC, Singh M, Formica R, . Renal transplantation for nephrogenic systemic fibrosis: A case report and review of the literature. Nephrology Dialysis Transplantation. 2011;26(3):1099–1101.
50 Daram SR, Cortese CM, Bastani B. Nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis: report of a new case with literature review. Am J Kidney Dis. 2005;46(4):754–9.16183432
51 Dawn G, Holmes SC. Scleromyxoedema-like eruption following haemodialysis or nephrogenic fibrosing dermopathy? Br J Dermatol. 2004;150(1):167–8.14746646
52 de Kerviler E, Maravilla K, Meder JF, . Adverse Reactions to Gadoterate Meglumine: Review of Over 25 Years of Clinical Use and More Than 50 Million Doses. Invest Radiol. 2016;51(9):544–51.27504794
53 Deng A, Martin DB, Spillane A, . Nephrogenic systemic fibrosis with a spectrum of clinical and histopathological presentation: a disorder of aberrant dermal remodeling. J Cutan Pathol. 2010;37(2):204–10.19341434
54 Deng AC, Bilu DM, Sina B, . Localized nephrogenic fibrosing dermopathy: Aberrant dermal repairing? J Am Acad Dermatol. 2008;58(2):336–339.18222333
55 Deo A, Fogel M, Cowper SE. Nephrogenic systemic fibrosis: a population study examining the relationship of disease development to gadolinium exposure. Clin J Am Soc Nephrol. 2007;2(2):264–7.17699423
56 Dewan A, Zwerner J, Abraham JL, . Chronic, dusky, indurated plaques on the legs of a 31-year-old woman. Clin Exp Dermatol. 2016;41(3):328–330.26411642
57 Dhungel A, Lattupalli R, Topf J. Nephrogenic fibrosing dermopathy. ScientificWorldJournal. 2008;8:164–5.18264634
58 Do JG, Kim YB, Lee DG, . A case of delayed onset nephrogenic systemic fibrosis after gadolinium based contrast injection. Ann Rehabil Med. 2012;36(6):880–6.23342325
59 Duffy KL, Green L, Harris R, . Treatment of nephrogenic systemic fibrosis with Re-PUVA. J Am Acad Dermatol. 2008;59(2 Suppl 1):S39–40.18625379
60 Dundova I, Treska V, Simanek V, . Nephrogenic fibrosing dermopathy: a case study. Transplant Proc. 2005;37(10):4187–90.16387074
61 Dupont A, Majithia V, Ahmad S, . Nephrogenic fibrosing dermopathy, a new mimicker of systemic sclerosis. Am J Med Sci. 2005;330(4):192–4.16234612
62 Edgar E, Woltjer R, Whitham R, . Nephrogenic systemic fibrosis presenting as myopathy: a case report with histopathologic correlation. Neuromuscul Disord. 2010;20(6):411–3.20462761
63 Edsall LC, English JC, 3rd, Teague MW, . Calciphylaxis and metastatic calcification associated with nephrogenic fibrosing dermopathy. J Cutan Pathol. 2004;31(3):247–53.14984577
64 Edward M, Quinn JA, Burden AD, . Effect of different classes of gadolinium-based contrast agents on control and nephrogenic systemic fibrosis-derived fibroblast proliferation. Radiology. 2010;256(3):735–43.20663970
65 Elmholdt TR, Jorgensen B, Ramsing M, . Two cases of nephrogenic systemic fibrosis after exposure to the macrocyclic compound gadobutrol. NDT Plus. 2010;3(3):285–287.28657062
66 Endrikat J, Schwenke C, Prince MR. Gadobutrol for contrast-enhanced magnetic resonance imaging in elderly patients: review of the safety profile from clinical trial, post-marketing surveillance, and pharmacovigilance data. Clin Radiol. 2015;70(7):743–51.25933719
67 Endrikat J, Vogtlaender K, Dohanish S, . Safety of Gadobutrol: Results From 42 Clinical Phase II to IV Studies and Postmarketing Surveillance After 29 Million Applications. Invest Radiol. 2016;51(9):537–43.26964075
68 Evenepoel P, Zeegers M, Segaert S, . Nephrogenic fibrosing dermopathy: a novel, disabling disorder in patients with renal failure. Nephrol Dial Transplant. 2004;19(2):469–73.14736976
69 Ferner RE. What’s new in…: Adverse drug reactions. Medicine. 2011;39(4):239–241.
70 Fingerhut S, Sperling M, Holling M, . Gadolinium-based contrast agents induce gadolinium deposits in cerebral vessel walls, while the neuropil is not affected: an autopsy study. Acta Neuropathol. 2018;136(1):127–138.29748901
71 Firoz BF, Hunzeker CM, Soldano AC, . Nephrogenic fibrosing dermopathy. Dermatol Online J. 2008;14(5):11.
72 Foss C, Smith JK, Ortiz L, . Gadolinium-associated nephrogenic systemic fibrosis in a 9-year-old boy. Pediatr Dermatol. 2009;26(5):579–82.19840315
73 Friedman SL. Focus. Journal of Hepatology. 2012;57(3):481–483.22691572
74 Fuah KW, Lim CTS. Erythema nodosum masking nephrogenic systemic fibrosis as initial skin manifestation. BMC Nephrol. 2017;18(1):249.28738858
75 Gambichler T, Paech V, Kreuter A, . Nephrogenic fibrosing dermopathy. Clin Exp Dermatol. 2004;29(3):258–60.15115505
76 George DE, Lu R, George SJ, . Nephrogenic fibrosing dermopathy: case report and review. Dermatol Online J. 2006;12(3):7.
77 Gharacholou SM, Maleszewski JJ, Borlaug BA, . “Carcinoid-like” tricuspid valvulopathy associated with nephrogenic systemic fibrosis. Echocardiography. 2011;28(3):E46–9.21366687
78 Gibson SE, Farver CF, Prayson RA. Multiorgan involvement in nephrogenic fibrosing dermopathy: an autopsy case and review of the literature. Arch Pathol Lab Med. 2006;130(2):209–12.16454565
79 Giersig C. Nephrogenic systemic fibrosis as an adverse drug reaction of gadolinium-based contrast media for magnetic resonance imaging. Radiologe. 2007;47(9):794–799.17713753
80 Gilliet M, Cozzio A, Burg G, . Successful treatment of three cases of nephrogenic fibrosing dermopathy with extracorporeal photopheresis. Br J Dermatol. 2005;152(3):531–6.15787823
81 Glaich AS, Martinelli PT, Markus RF, . Generalized elastolysis following nephrogenic fibrosing dermopathy. J Am Acad Dermatol. 2005;53(1):174–6.15965449
82 Goddard DS, Magee CC, Lazar AJ, . Nephrogenic fibrosing dermopathy with recurrence after allograft failure. J Am Acad Dermatol. 2007;56:(5 Suppl):S109–11.17434031
83 Granata V, Cascella M, Fusco R, . Immediate Adverse Reactions to Gadolinium-Based MR Contrast Media: A Retrospective Analysis on 10,608 Examinations. Biomed Res Int. 2016;2016:3918292.27652261
84 Grand DJ, Harris A, Loftus EV. Imaging for Luminal Disease and Complications: CT Enterography, MR Enterography, Small-Bowel Follow-Through, and Ultrasound. Gastroenterology Clinics of North America. 2012;41(2):497–512.22500531
85 Grebe SO, Borrmann M, Altenburg A, . Chronic inflammation and accelerated atherosclerosis as important cofactors in nephrogenic systemic fibrosis following intravenous gadolinium exposure. Clin Exp Nephrol. 2008;12(5):403–406.18551245
86 Grobner T. Gadolinium-a specific trigger for the development of nephrogenic fibrosing dermopathy and nephrogenic systemic fibrosis? Nephrol Dial Transplant. 2006;21(4):1104–8.16431890
87 Gulati A, Harwood CA, Raftery M, . Magnetic resonance imaging with gadolinium enhancement in renal failure: a need for caution. Int J Dermatol. 2008;47(9):947–9.18937660
88 Gutierrez JE, Koenig S, Breuer J. Overview on the efficacy and safety of gadobutrol: An MRI contrast agent for the CNS, body and vessels. Imaging in Medicine. 2012;4(1):25–40.
89 Gutierrez JE, Rosenberg M, Duhaney M, . Phase 3 efficacy and safety trial of gadobutrol, a 1.0 molar macrocyclic MR imaging contrast agent, in patients referred for contrast-enhanced MR imaging of the central nervous system. J Magn Reson Imaging. 2015;41(3):788–96.24578298
90 Gutierrez JE, Rosenberg M, Seemann J, . Safety and Efficacy of Gadobutrol for Contrast-enhanced Magnetic Resonance Imaging of the Central Nervous System: Results from a Multicenter, Double-blind, Randomized, Comparator Study. Magn Reson Insights. 2015;8:1–10.
91 Hall ME, Miller CD, Hundley WG. Adenosine stress cardiovascular magnetic resonance-observation unit management of patients at intermediate risk for acute coronary syndrome: A possible strategy for reducing healthcare-related costs. Current Treatment Options in Cardiovascular Medicine. 2012;14(1):117–125.22127744
92 Haller C, James LP. Adverse drug reactions: Moving from chance to science. Clin Pharmacol Ther. 2011;89(6):761–764.21593747
93 Halteh P, Huang J, Wildman HF, . Gadolinium-Naive Nephrogenic Systemic Fibrosis of Breast Mimicking Inflammatory Breast Carcinoma. Am J Dermatopathol. 2017;39(4):322–324.28323787
94 Hamilton BE, Nesbit GM, Dosa E, . Comparative analysis of ferumoxytol and gadoteridol enhancement using T1- and T2-weighted MRI in neuroimaging. American Journal of Roentgenology. 2011;197(4):981–988.21940589
95 Hanna RF, Finkelstone LA, Chow DS, . Nephrogenic systemic fibrosis risk and liver disease. Int J Nephrol. 2014;2014:679605.24778878
96 Hashemi P, Sina B, Rietkerk W, . The debate between gadolinium versus erythropoietin in a renal transplant patient with nephrogenic systemic fibrosis. J Nephrol. 2013;26(1):48–54.22573525
97 Hauser C, Kaya G, Chizzolini C. Nephrogenic fibrosing dermopathy in a renal transplant recipient with tubulointerstitial nephritis and uveitis. Dermatology. 2004;209(1):50–2.15237268
98 He A, Kwatra SG, Zampella JG, . Nephrogenic systemic fibrosis: fibrotic plaques and contracture following exposure to gadolinium-based contrast media. BMJ Case Rep. 2016;2016.
99 Hedley AJ, Molan MP, Hare DL, . Nephrogenic systemic fibrosis associated with gadolinium-containing contrast media administration in patients with reduced glomerular filtration rate. Australas Radiol. 2007;51(3):300.
100 Hedley AJ, Molan MP, Hare DL, . Nephrogenic systemic fibrosis associated with gadolinium-containing contrast media administration in patients with reduced glomerular filtration rate. Nephrology (Carlton). 2007;12(1):111.17295674
101 Heinz-Peer G, Neruda A, Watschinger B, . Prevalence of NSF following intravenous gadolinium-contrast media administration in dialysis patients with endstage renal disease. Eur J Radiol. 2010;76(1):129–34.19619969
102 Hickson LJ, Bundrick JB, Litin SC. Clinical pearls in nephrology. Mayo Clinic Proceedings. 2010;85(11):1046–1050.21037047
103 Hidalgo Parra I, Torre A, Galimberti G, . Nephrogenic fibrosing dermopathy. J Eur Acad Dermatol Venereol. 2008;22(7):875–6.18462299
104 High WA, Ayers RA, Chandler J, . Gadolinium is detectable within the tissue of patients with nephrogenic systemic fibrosis. J Am Acad Dermatol. 2007;56(1):21–6.17097388
105 High WA, Ayers RA, Cowper SE. Gadolinium is quantifiable within the tissue of patients with nephrogenic systemic fibrosis. J Am Acad Dermatol. 2007;56(4):710–712.17289213
106 Hodnett PA, Ward EV, Davarpanah AH, . Peripheral arterial disease in a symptomatic diabetic population: prospective comparison of rapid unenhanced MR angiography (MRA) with contrast-enhanced MRA. AJR Am J Roentgenol. 2011;197(6):1466–73.22109304
107 Homayoon B, Diwakar H, Strovski E, . Half-dose gadobenate dimeglumine versus standard-dose gadodiamide in dynamic magnetic resonance imaging of non-cirrhotic livers: a retrospective intra-individual crossover comparison. Abdominal Imaging. 2014.
108 Hong TS, Greer MLC, Grosse-Wortmann L, . Whole-body MR angiography: Initial experience in imaging pediatric vasculopathy. Pediatr Radiol. 2011;41(6):769–778.21249351
109 Hope TA, Herfkens RJ, Denianke KS, . Nephrogenic systemic fibrosis in patients with chronic kidney disease who received gadopentetate dimeglumine. Invest Radiol. 2009;44(3):135–9.19151610
110 Hubbard V, Davenport A, Jarmulowicz M, . Scleromyxoedema-like changes in four renal dialysis patients. Br J Dermatol. 2003;148(3):563–8.12653751
111 Hurley MC, Soltanolkotabi M, Ansari S. Neuroimaging in acute stroke: Choosing the right patient for neurointervention. Techniques in Vascular and Interventional Radiology. 2012;15(1):19–32.22464299
112 Introcaso CE, Elenitsas R, Xu X, . Periocular papules in nephrogenic systemic fibrosis. J Am Acad Dermatol. 2008;59(3):536–7.18625538
113 Introcaso CE, Hivnor C, Cowper S, . Nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis: a case series of nine patients and review of the literature. Int J Dermatol. 2007;46(5):447–52.17472669
114 Ishiguchi T, Takahashi S. Safety of gadoterate meglumine (Gd-DOTA) as a contrast agent for magnetic resonance imaging: results of a post-marketing surveillance study in Japan. Drugs R D. 2010;10(3):133–45.20945944
115 Jalandhara N, Arora R, Batuman V. Nephrogenic systemic fibrosis and gadolinium-containing radiological contrast agents: an update. Clin Pharmacol Ther. 2011;89(6):920–3.21471962
116 Jan F, Mahboob H, Schwartz AB. Quiz page February 2008: A hemodialysis patient with thickened skin. Nephrogenic fibrosing dermopathy. Am J Kidney Dis. 2008;51(2):A33–4.18215691
117 Jan F, Segal JM, Dyer J, . Nephrogenic fibrosing dermopathy: two pediatric cases. J Pediatr. 2003;143(5):678–81.14615747
118 Jikki PN. Nephrogenic systemic fibrosis: is gadolinium to be blamed? J Assoc Physicians India. 2008;56:915–6.19263697
119 Kafi R, Fisher GJ, Quan T, . UV-A1 phototherapy improves nephrogenic fibrosing dermopathy. Arch Dermatol. 2004;140(11):1322–4.15545539
120 Kalisz KR, Davarpanah AH, Usman AA, . Detection of renal dysfunction by point-of-care creatinine testing in patients undergoing peripheral MR angiography. AJR Am J Roentgenol. 2011;197(2):430–5.21785090
121 Kanda T, Osawa M, Oba H, . High Signal Intensity in Dentate Nucleus on Unenhanced T1-weighted MR Images: Association with Linear versus Macrocyclic Gadolinium Chelate Administration. Radiology. 2015;275(3):803–9.25633504
122 Kartono F, Basile A, Roshdieh B, . Findings of osseous sclerotic bodies: a unique sequence of cutaneous bone formation in nephrogenic systemic fibrosis. J Cutan Pathol. 2011;38(3):286–9.20726931
123 Kaul A. Contrast-induced acute kidney injury. Clinical Queries: Nephrology. 2012;1(1):34–41.
124 Kay J, Bazari H, Avery LL, . A woman with renal failure and stiffness of the joints and skin - Nephrogenic systemic fibrosis, involving the skin, heart, lungs, diaphragm and psoas muscles, dura, and possibly the kidney. End-stage renal disease with nephrocalcinosis. Acute and organizing bronchopneumonia. New England Journal of Medicine. 2008;358(8):827–838.18287606
125 Kay J, High WA. Imatinib mesylate treatment of nephrogenic systemic fibrosis. Arthritis Rheum. 2008;58(8):2543–8.18668587
126 Kelly B, Petitt M, Sanchez R. Nephrogenic systemic fibrosis is associated with transforming growth factor β and Smad without evidence of renin-angiotensin system involvement. J Am Acad Dermatol. 2008;58(6):1025–1030.18485985
127 Kendrick-Jones JC, Voss DM, De Zoysa JR. Nephrogenic systemic fibrosis, in patients with end-stage kidney disease on dialysis, in the greater Auckland region, from 2000-2006. Nephrology (Carlton). 2011;16(2):243–8.21272139
128 Kennedy C, Magee C, Eltayeb E, . Nephrogenic systemic fibrosis. Ir Med J. 2010;103(7):208–10.20845600
129 Khor LK, Tan KB, Loi HY, . Nephrogenic systemic fibrosis in a patient with renal failure demonstrating a “reverse superscan” on bone scintigraphy. Clin Nucl Med. 2013;38(3):203–4.23354034
130 Khurana A, Greene JF, Jr., High WA. Quantification of gadolinium in nephrogenic systemic fibrosis: re-examination of a reported cohort with analysis of clinical factors. J Am Acad Dermatol. 2008;59(2):218–24.18538448
131 Khurram M, Skov L, Rossen K, . Nephrogenic systemic fibrosis: a serious iatrogenic disease of renal failure patients. Scand J Urol Nephrol. 2007;41(6):565–6.17934986
132 Kim RH, Ma L, Hayat SQ, . Nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis in 2 patients with end-stage renal disease on hemodialysis. J Clin Rheumatol. 2006;12(3):134–6.16755242
133 Kitaura K, Harima K, Inami N, . Prolonged dural enhancement by iodine contrast agent mimicking subdural haematoma in a patient with nephrogenic systemic fibrosis. NDT Plus. 2010;3(2):193–194.
134 Knapp BA, Sepahpanah F. Nephrogenic systemic fibrosis in a patient with spinal cord injury: a unique case presentation. Pm r. 2010;2(12):1141–4.21145526
135 Koratala A, Bhatti V. Nephrogenic systemic fibrosis. Clin Case Rep. 2017;5(7):1184–1185.28680623
136 Koreishi AF, Nazarian RM, Saenz AJ, . Nephrogenic systemic fibrosis: a pathologic study of autopsy cases. Arch Pathol Lab Med. 2009;133(12):1943–8.19961249
137 Kraetschmer K. Gadolinium-induced nephrogenic systemic fibrosis: communication breakdown among specialists or intuitive stroke of genius? Intern Med J. 2009;39(1):70–2.
138 Kramer H, Runge VM, Morelli JN, . Magnetic resonance angiography of the carotid arteries: Comparison of unenhanced and contrast enhanced techniques. Eur Radiol. 2011;21(8):1667–1676.21476128
139 Kreuter A, Gambichler T, Weiner SM, . Limited effects of UV-A1 phototherapy in 3 patients with nephrogenic systemic fibrosis. Arch Dermatol. 2008;144(11):1527–9.19015438
140 Krishnamurthy R, Lee E. Congenital Cardiovascular Malformations: Noninvasive Imaging by MRI in Neonates. Magn Reson Imaging Clin N Am. 2011;19(4):813–822.22082739
141 Kroshinsky D, Kay J, Nazarian RM. Case records of the Massachusetts General Hospital. Case 37-2009. A 46-year-old woman with chronic renal failure, leg swelling, and skin changes. N Engl J Med. 2009;361(22):2166–76.19940302
142 Krous HF, Breisch E, Chadwick AE, . Nephrogenic systemic fibrosis with multiorgan involvement in a teenage male after lymphoma, Ewing’s sarcoma, end-stage renal disease, and hemodialysis. Pediatric and Developmental Pathology. 2007;10(5):395–402.17929984
143 Kucher C, Steere J, Elenitsas R, . Nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis with diaphragmatic involvement in a patient with respiratory failure. J Am Acad Dermatol. 2006;54:(2 Suppl):S31–4.16427988
144 Kunst MM, Schaefer PW. Ischemic stroke. Radiol Clin North Am. 2011;49(1):1–26.21111127
145 Larson KN, Gagnon AL, Darling MD, . Nephrogenic Systemic Fibrosis Manifesting a Decade After Exposure to Gadolinium. JAMA Dermatol. 2015;151(10):1117–20.26017458
146 Lauenstein TC, Salman K, Morreira R, . Nephrogenic systemic fibrosis: center case review. J Magn Reson Imaging. 2007;26(5):1198–203.17969162
147 Learned KO, Adappa ND, Loevner LA, . MR imaging evaluation of endoscopic cranial base reconstruction with pedicled nasoseptal flap following endoscopic endonasal skull base surgery. Eur J Radiol. 2013;82(3):544–551.23219190
148 LeBoit PE. What nephrogenic fibrosing dermopathy might be. Arch Dermatol. 2003;139(7):928–30.12873893
149 Lee CU, Wood CM, Hesley GK, . Large sample of nephrogenic systemic fibrosis cases from a single institution. Arch Dermatol. 2009;145(10):1095–102.19841395
150 Lee CS, Lewin JS, Nagy P. Events that have shaped the quality movement in radiology. Journal of the American College of Radiology. 2012;9(6):437–439.22632673
151 Leiner T, Kucharczyk W. Special issue: nephrogenic systemic fibrosis. J Magn Reson Imaging. 2009;30(6):1233–5.19938034
152 Lemy AA, del Marmol V, Kolivras A, . Revisiting nephrogenic systemic fibrosis in 6 kidney transplant recipients: a single-center experience. J Am Acad Dermatol. 2010;63(3):389–99.20619488
153 Leung N, Pittelkow MR, Lee CU, . Chelation of gadolinium with deferoxamine in a patient with nephrogenic systemic fibrosis. NDT Plus. 2009;2(4):309–11.25984024
154 Levine JM, Taylor RA, Elman LB, . Involvement of skeletal muscle in dialysis-associated systemic fibrosis (nephrogenic fibrosing dermopathy). Muscle Nerve. 2004;30(5):569–77.15389718
155 Lewis KG, Lester BW, Pan TD, . Nephrogenic fibrosing dermopathy and calciphylaxis with pseudoxanthoma elasticum-like changes. J Cutan Pathol. 2006;33(10):695–700.17026522
156 Lim YL, Lee HY, Low SC, . Possible role of gadolinium in nephrogenic systemic fibrosis: report of two cases and review of the literature. Clin Exp Dermatol. 2007;32(4):353–8.17433041
157 Lu CF, Hsiao CH, Tjiu JW. Nephrogenic systemic fibrosis developed after recovery from acute renal failure: gadolinium as a possible aetiological factor. J Eur Acad Dermatol Venereol. 2009;23(3):339–40.18573157
158 Mackay-Wiggan JM, Cohen DJ, Hardy MA, . Nephrogenic fibrosing dermopathy (scleromyxedema-like illness of renal disease). J Am Acad Dermatol. 2003;48(1):55–60.12522371
159 Marckmann P, Nielsen AH, Sloth JJ. Possibly enhanced Gd excretion in dialysate, but no major clinical benefit of 3-5 months of treatment with sodium thiosulfate in late stages of nephrogenic systemic fibrosis. Nephrol Dial Transplant. 2008;23(10):3280–2.18436563
160 Markus JS, James AJ, Nunez-Gussman JK, . Nephrogenic fibrosing dermopathy. J Am Acad Dermatol. 2005;52(1):166–7.15627104
161 Martin DR. Nephrogenic systemic fibrosis. Pediatr Radiol. 2008;38: Suppl 1:S125–9.18071694
162 Martin DR, Kalb B, Mittal A, . No incidence of nephrogenic systemic fibrosis after gadobenate dimeglumine administration in patients undergoing dialysis or those with severe chronic kidney disease. Radiology. 2018;286(1):113–119.28731375
163 Mathur K, Morris S, Deighan C, . Extracorporeal photopheresis improves nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis: three case reports and review of literature. J Clin Apher. 2008;23(4):144–50.18633995
164 Matich SM. Just pediatrics: Kids, contrast media, contrast-induced nephropathy, and nephrogenic systemic fibrosis. Journal of Radiology Nursing. 2014;33(2):88–89.
165 Matsumoto Y, Mitsuhashi Y, Monma F, . Nephrogenic systemic fibrosis: a case report and review on Japanese patients. J Dermatol. 2012;39(5):449–53.22035371
166 Mavrogeni S, Vassilopoulos D. Is There a Place for Cardiovascular Magnetic Resonance Imaging in the Evaluation of Cardiovascular Involvement in Rheumatic Diseases? Seminars in Arthritis and Rheumatism. 2011;41(3):488–496.21641017
167 Mazhar SM, Shiehmorteza M, Kohl CA, . Nephrogenic systemic fibrosis in liver disease: a systematic review. J Magn Reson Imaging. 2009;30(6):1313–22.19937937
168 McNeill AM, Barr RJ. Scleromyxedema-like fibromucinosis in a patient undergoing hemodialysis. Int J Dermatol. 2002;41(6):364–7.12100695
169 Mendoza FA, Artlett CM, Sandorfi N, . Description of 12 cases of nephrogenic fibrosing dermopathy and review of the literature. Semin Arthritis Rheum. 2006;35(4):238–49.16461069
170 Mihai G, Simonetti OP, Thavendiranathan P. Noncontrast MRA for the Diagnosis of Vascular Diseases. Cardiology Clinics. 2011;29(3):341–350.21803224
171 Miyamoto J, Tanikawa A, Igarashi A, . Detection of iron deposition in dermal fibrocytes is a useful tool for histologic diagnosis of nephrogenic systemic fibrosis. Am J Dermatopathol. 2011;33(3):271–6.21389836
172 Mohidin B. Skin changes after a magnetic resonance imaging scan. Bmj. 2018;360:k77.29437683
173 Morcos SK. Experimental studies investigating the pathophysiology of nephrogenic systemic fibrosis; what did we learn so far? Eur Radiol. 2011;21(3):496–500.20848109
174 Moreno-Romero JA, Segura S, Mascaro JM, Jr., . Nephrogenic systemic fibrosis: a case series suggesting gadolinium as a possible aetiological factor. Br J Dermatol. 2007;157(4):783–7.17627792
175 Moschella SL, Kay J, Mackool BT, . Case records of the Massachusetts General Hospital. Weekly clinicopathological exercises. Case 35-2004. A 68-year-old man with end-stage renal disease and thickening of the skin. N Engl J Med. 2004;351(21):2219–27.15548783
176 Murata N, Gonzalez-Cuyar LF, Murata K, . Macrocyclic and Other Non-Group 1 Gadolinium Contrast Agents Deposit Low Levels of Gadolinium in Brain and Bone Tissue: Preliminary Results From 9 Patients With Normal Renal Function. Invest Radiol. 2016;51(7):447–53.26863577
177 Nakai K, Takeda K, Kimura H, . Nephrogenic systemic fibrosis in a patient on long-term hemodialysis. Clin Nephrol. 2009;71(2):217–20.19203520
178 Nardone B, Saddleton E, Laumann AE, . Pediatric nephrogenic systemic fibrosis is rarely reported: a RADAR report. Pediatr Radiol. 2014;44(2):173–80.24057195
179 Nazarian RM, Mandal RV, Kagan A, . Quantitative assessment of dermal cellularity in nephrogenic systemic fibrosis: a diagnostic aid. J Am Acad Dermatol. 2011;64(4):741–7.21414498
180 Nguyen KL, Bandettini WP, Shanbhag S, . Safety and tolerability of regadenoson CMR. European Heart Journal Cardiovascular Imaging. 2014;15(7):753–760.24451179
181 Nielsen YJW. Whole-body MR angiography in patients with peripheral arterial disease. Danish Medical Bulletin. 2010;57(12).
182 Obermoser G, Emberger M, Wieser M, . Nephrogenic fibrosing dermopathy in two patients with systemic lupus erythematosus. Lupus. 2004;13(8):609–12.15462493
183 Okada S, Katagiri K, Kumazaki T, . Safety of gadolinium contrast agent in hemodialysis patients. Acta Radiol. 2001;42(3):339–41.11350296
184 Ota T, Kimura J, Ishiguchi T. Safety and clinical usefulness of gadoteric acid including post-marketing surveillance. Imaging in Medicine. 2012;4(4):397–409.
185 Othersen JB, Maize JC, Woolson RF, . Nephrogenic systemic fibrosis after exposure to gadolinium in patients with renal failure. Nephrol Dial Transplant. 2007;22(11):3179–85.17890246
186 Pagel MD. Responsive paramagnetic chemical exchange saturation transfer MRI contrast agents. Imaging in Medicine. 2011;3(4):377–380.30854026
187 Panda S, Bandyopadhyay D, Tarafder A. Nephrogenic fibrosing dermopathy: a series in a non-Western population. J Am Acad Dermatol. 2006;54(1):155–9.16384776
188 Panesar M, Banerjee S, Barone GW. Clinical improvement of nephrogenic systemic fibrosis after kidney transplantation. Clin Transplant. 2008;22(6):803–8.18713261
189 Pao VY, Chang S, Shoback DM, . Hypercalcemia and overexpression of CYP27B1 in a patient with nephrogenic systemic fibrosis: clinical vignette and literature review. J Bone Miner Res. 2009;24(6):1135–9.19113910
190 Penfield JG, Reilly RF. Nephrogenic systemic fibrosis risk: is there a difference between gadolinium-based contrast agents? Semin Dial. 2008;21(2):129–34.18225999
191 Perazella MA. Nephrogenic systemic fibrosis, kidney disease, and gadolinium: is there a link? Clin J Am Soc Nephrol. 2007;2(2):200–2.17699407
192 Perazella MA, Ishibe S, Perazella MA, . Nephrogenic fibrosing dermopathy: an unusual skin condition associated with kidney disease. Semin Dial. 2003;16(3):276–80.12753692
193 Perazella MA, Rodby RA. Nephrogenic systemic fibrosis: A devastating complication of gadolinium in patients with severe renal impairment. Vascular Disease Management. 2007;4(2):45–47.
194 Perez-Rodriguez J, Lai S, Ehst BD, . Nephrogenic systemic fibrosis: incidence, associations, and effect of risk factor assessment-report of 33 cases. Radiology. 2009;250(2):371–7.19188312
195 Pieringer H, Schumacher S, Schmekal B, . Gadolinium-based contrast agents, erythropoietin and nephrogenic systemic fibrosis in patients with end-stage renal failure. NDT Plus. 2008;1(3):193–4.25983879
196 Prince MR, Zhang H, Zou Z, . Incidence of immediate gadolinium contrast media reactions. AJR Am J Roentgenol. 2011;196(2):W138–43.21257854
197 Pryor JG, Poggioli G, Galaria N, . Nephrogenic systemic fibrosis: a clinicopathologic study of six cases. J Am Acad Dermatol. 2007;57(1):105–11.17412451
198 Radbruch A, Weberling LD, Kieslich PJ, . Gadolinium retention in the dentate nucleus and globus pallidus is dependent on the class of contrast agent. Radiology. 2015;275(3):783–91.25848905
199 Ray JG, Vermeulen MJ, Bharatha A, . Association Between MRI Exposure During Pregnancy and Fetal and Childhood Outcomes. Jama. 2016;316(9):952–61.27599330
200 Riccabona M, Olsen OE, Claudon M, . Gadolinium and Nephrogenic Systemic Fibrosis. Pediatric Uroradiology, 2nd Edition; 2008:515–517.
201 Roberts DR, Lindhorst SM, Welsh CT, . High Levels of Gadolinium Deposition in the Skin of a Patient With Normal Renal Function. Invest Radiol. 2016;51(5):280–9.26953564
202 Robinson MR, Routhouska SB, Paspulati RM, . Alefacept therapy for nephrogenic systemic fibrosis: a case series. J Drugs Dermatol. 2011;10(8):922–4.21818517
203 Rodby RA. Can gadolinium be given safely to a patient on dialysis? Semin Dial. 2011;24(4):370–1.21801214
204 Ross C, De Rosa N, Marshman G, . Nephrogenic systemic fibrosis in a gadolinium-naive patient: successful treatment with oral sirolimus. Australas J Dermatol. 2015;56(3):e59–62.25330850
205 Ruiz-Genao DP, Pascual-Lopez MP, Fraga S, . Osseous metaplasia in the setting of nephrogenic fibrosing dermopathy. J Cutan Pathol. 2005;32(2):172–5.15606678
206 Rydahl C, Thomsen HS, Marckmann P. High prevalence of nephrogenic systemic fibrosis in chronic renal failure patients exposed to gadodiamide, a gadolinium-containing magnetic resonance contrast agent. Invest Radiol. 2008;43(2):141–4.18197066
207 Saenz A, Mandal R, Kradin R, . Nephrogenic fibrosing dermopathy with involvement of the dura mater. Virchows Arch. 2006;449(3):389–91.16896891
208 Sambol EB, Van der Meer JG, Graham A, . The use of gadolinium for arterial interventions. Ann Vasc Surg. 2011;25(3):366–76.21288688
209 Sanchez-Ross M, Snyder R, Colome-Grimmer MI, . Nephrogenic fibrosing dermopathy in a patient with systemic lupus erythematosus and acute lupus nephritis. Pediatr Dermatol. 2007;24(5):E36–9.17958777
210 Sanyal S, Marckmann P, Scherer S, . Multiorgan gadolinium (Gd) deposition and fibrosis in a patient with nephrogenic systemic fibrosis--an autopsy-based review. Nephrol Dial Transplant. 2011;26(11):3616–26.21441397
211 Saussereau E, Lacroix C, Cattaneo A, . Hair and fingernail gadolinium ICP-MS contents in an overdose case associated with nephrogenic systemic fibrosis. Forensic Sci Int. 2008;176(1):54–7.17983714
212 Schieren G, Wirtz N, Altmeyer P, . Nephrogenic systemic fibrosis-a rapidly progressive disabling disease with limited therapeutic options. J Am Acad Dermatol. 2009;61(5):868–74.19836645
213 Schietinger BJ, Brammer GM, Wang H, . Patterns of late gadolinium enhancement in chronic hemodialysis patients. JACC Cardiovasc Imaging. 2008;1(4):450–6.19356466
214 Schleichert RA, Seliger SL, Zhan M, . Nephrogenic systemic fibrosis and diabetes mellitus. Arch Dermatol. 2012;148(2):255–7.22351833
215 Schmiedl S, Wesselmann U, Lehmann P, . Different time courses of nephrogenic systemic fibrosis: Is there a role for pharmacokinetic aspects in explaining a new clinical entity? Int J Clin Pharmacol Ther. 2009;47(11):695–700.19840534
216 Schmook T, Budde K, Ulrich C, . Successful treatment of nephrogenic fibrosing dermopathy in a kidney transplant recipient with photodynamic therapy. Nephrol Dial Transplant. 2005;20(1):220–2.15632355
217 Schneider G, Ballarati C, Grazioli L, . Gadobenate dimeglumine-enhanced MR angiography: Diagnostic performance of four doses for detection and grading of carotid, renal, and aorto-iliac stenoses compared to digital subtraction angiography. Journal of Magnetic Resonance Imaging. 2007;26(4):1020–1032.17896354
218 Schroeder JA, Weingart C, Coras B, . Ultrastructural evidence of dermal gadolinium deposits in a patient with nephrogenic systemic fibrosis and end-stage renal disease. Clin J Am Soc Nephrol. 2008;3(4):968–75.18385397
219 Sego S. Nephrogenic fibrosing dermopathy: a case study. Nephrol Nurs J. 2008;35(1):67–8.18372766
220 Semelka RC, Ramalho J, Vakharia A, . Gadolinium deposition disease: Initial description of a disease that has been around for a while. Magn Reson Imaging. 2016;34(10):1383–1390.27530966
221 Shabana WM, Cohan RH, Ellis JH, . Nephrogenic systemic fibrosis: a report of 29 cases. AJR Am J Roentgenol. 2008;190(3):736–41.18287446
222 Shah AH, Olivero JJ. Gadolinium-Induced Nephrogenic Systemic Fibrosis. Methodist Debakey Cardiovasc J. 2017;13(3):172–173.29744004
223 Sharfuddin A. Imaging evaluation of kidney transplant recipients. Semin Nephrol. 2011;31(3):259–271.21784275
224 Sharma J, Mongia A, Schoenaman M, . Nephrogenic fibrosing dermatopathy, cardiac calcification and pulmonary hypertension in an adolescent on chronic hemodialysis. Indian J Nephrol. 2008;18(2):70–3.20142906
225 Shimoji K, Aoki S, Nakanishi A, . Distribution of estimated glomerular filtration rate (eGFR) values in patients receiving contrast-enhanced magnetic resonance imaging. Jpn J Radiol. 2012;30(2):116–9.22200915
226 Singh M, Davenport A, Clatworthy I, . A follow-up of four cases of nephrogenic systemic fibrosis: is gadolinium the specific trigger? Br J Dermatol. 2008;158(6):1358–62.18363754
227 So K, Macquillan GC, Adams LA, . Malignant fibrous histiocytoma complicating nephrogenic systemic fibrosis post liver transplantation. Intern Med J. 2009;39(9):613–7.19769682
228 Solomon GJ, Wu E, Rosen PP. Nephrogenic systemic fibrosis mimicking inflammatory breast carcinoma. Arch Pathol Lab Med. 2007;131(1):145–8.17227116
229 Soulez G, Pasowicz M, Benea G, . Renal artery stenosis evaluation: Diagnostic performance of gadobenate dimeglumine-enhanced MR angiography - Comparison with DSA. Radiology. 2008;247(1):273–285.18372471
230 Steen H, Giannitsis E, Sommerer C, . Acute phase reaction to gadolinium-DTPA in dialysis patients. Nephrol Dial Transplant. 2009;24(4):1274–7.19042926
231 Streams BN, Liu V, Liegeois N, . Clinical and pathologic features of nephrogenic fibrosing dermopathy: a report of two cases. J Am Acad Dermatol. 2003;48(1):42–7.12522369
232 Su HS, Nazarian RM, Scott JA. Case report. Appearance of nephrogenic fibrosing dermopathy on a bone scan. Br J Radiol. 2009;82(974):e35–6.19168688
233 Su HS, Nazarian RM, Scott JA. Appearance of nephrogenic fibrosing dermopathy on a bone scan. British Journal of Radiology. 2009;82(974):e35–e36.19168688
234 Swaminathan S, High WA, Ranville J, . Cardiac and vascular metal deposition with high mortality in nephrogenic systemic fibrosis. Kidney Int. 2008;73(12):1413–8.18401336
235 Tan AW, Tan SH, Lian TY, . A case of nephrogenic fibrosing dermopathy. Ann Acad Med Singapore. 2004;33(4):527–9.15329770
236 Tanaka A, Masumoto T, Yamada H, . A Japanese, Multicenter, Open-label, Phase 3 Study to Investigate the Safety and Efficacy of Gadobutrol for Contrast-enhanced MR Imaging of the Central Nervous System. Magn Reson Med Sci. 2016;15(2):227–36.26687097
237 Thakral C, Abraham JL. Gadolinium-induced nephrogenic systemic fibrosis is associated with insoluble Gd deposits in tissues: in vivo transmetallation confirmed by microanalysis. J Cutan Pathol. 2009;36(12):1244–54.19602073
238 Thakral C, Alhariri J, Abraham JL. Long-term retention of gadolinium in tissues from nephrogenic systemic fibrosis patient after multiple gadolinium-enhanced MRI scans: case report and implications. Contrast Media Mol Imaging. 2007;2(4):199–205.17712863
239 Thomsen HS. Nephrogenic systemic fibrosis: A serious late adverse reaction to gadodiamide. Eur Radiol. 2006;16(12):2619–21.17061066
240 Thomsen HS, Marckmann P. Extracellular Gd-CA: differences in prevalence of NSF. Eur J Radiol. 2008;66(2):180–3.18342468
241 Thomsen HS, Morcos SK. A european view-point on NSF. Current Rheumatology Reviews. 2010;6(3):184–188.
242 Thomsen HS, Morcos SK, Dawson P. Is there a causal relation between the administration of gadolinium based contrast media and the development of nephrogenic systemic fibrosis (NSF)? Clin Radiol. 2006;61(11):905–6.17018301
243 Thomson LK, Thomson PC, Kingsmore DB, . Diagnosing nephrogenic systemic fibrosis in the post-FDA restriction era. J Magn Reson Imaging. 2015;41(5):1268–71.24903851
244 Thurnher S, Miller S, Schneider G, . Diagnostic performance of gadobenate dimeglumine-enhanced MR angiography of the iliofemoral and calf arteries: A large-scale multicenter trial. American Journal of Roentgenology. 2007;189(5):1223–1237.17954665
245 Ting WW, Stone MS, Madison KC, . Nephrogenic fibrosing dermopathy with systemic involvement. Arch Dermatol. 2003;139(7):903–6.12873886
246 Todd DJ, Kagan A, Chibnik LB, . Cutaneous changes of nephrogenic systemic fibrosis: predictor of early mortality and association with gadolinium exposure. Arthritis Rheum. 2007;56(10):3433–41.17907148
247 Tsai CW, Chao CC, Wu VC, . Nephrogenic fibrosing dermopathy in a peritoneal dialysis patient. Kidney Int. 2007;72(10):1294.17972912
248 Tsushima Y, Takahashi-Taketomi A, Endo K. Nephrogenic systemic fibrosis in Japan: advisability of keeping the administered dose as low as possible. Radiology. 2008;247(3):915–6.18487548
249 Ustuner P, Kose OK, Gulec AT, . A moderate response to plasmapheresis in nephrogenic systemic fibrosis. Clin Pract. 2011;1(4):e124.24765365
250 Valsangiacomo Buechel ER, Fogel MA. Congenital Cardiac Defects and MR-Guided Planning of Surgery. Magn Reson Imaging Clin N Am. 2011;19(4):823–840.22082740
251 Voth M, Rosenberg M, Breuer J. Safety of gadobutrol, a new generation of contrast agents: experience from clinical trials and postmarketing surveillance. Invest Radiol. 2011;46(11):663–71.21623211
252 Wahba IM, Simpson EL, White K. Gadolinium is not the only trigger for nephrogenic systemic fibrosis: insights from two cases and review of the recent literature. Am J Transplant. 2007;7(10):2425–32.17711550
253 Wang Y, Alkasab TK, Narin O, . Incidence of nephrogenic systemic fibrosis after adoption of restrictive gadolinium-based contrast agent guidelines. Radiology. 2011;260(1):105–11.21586680
254 Weigle JP, Broome DR. Nephrogenic systemic fibrosis: chronic imaging findings and review of the medical literature. Skeletal Radiol. 2008;37(5):457–64.18324398
255 Weiss AS, Lucia MS, Teitelbaum I. A case of nephrogenic fibrosing dermopathy/nephrogenic systemic fibrosis. Nat Clin Pract Nephrol. 2007;3(2):111–5.17251999
256 Weller A, Barber JL, Olsen OE. Gadolinium and nephrogenic systemic fibrosis: an update. Pediatr Nephrol. 2014;29(10):1927–37.24146299
257 Wertman R, Altun E, Martin DR, . Risk of nephrogenic systemic fibrosis: evaluation of gadolinium chelate contrast agents at four American universities. Radiology. 2008;248(3):799–806.18632533
258 Wiginton CD, Kelly B, Oto A, . Gadolinium-based contrast exposure, nephrogenic systemic fibrosis, and gadolinium detection in tissue. AJR Am J Roentgenol. 2008;190(4):1060–8.18356456
259 Wilford C, Fine JD, Boyd AS, . Nephrogenic systemic fibrosis: report of an additional case with granulomatous inflammation. Am J Dermatopathol. 2010;32(1):71–5.19940755
260 Wilson J, Gleghorn K, Seigel Q, . Nephrogenic systemic fibrosis: A 15-year retrospective study at a single tertiary care center. J Am Acad Dermatol. 2017;77(2):235–240.28318680
261 Winship B, Ramakrishnan S, Evans J, . A single-center analysis of abdominal imaging in the evaluation of kidney transplant recipients. Clin Transplant. 2013;27(5):701–9.23941682
262 Woodard PK, Chenevert TL, Sostman HD, . Signal quality of single dose gadobenate dimeglumine pulmonary MRA examinations exceeds quality of MRA performed with double dose gadopentetate dimeglumine. Int J Cardiovasc Imaging. 2012;28(2):295–301.21337023
263 Yerram P, Saab G, Karuparthi PR, . Nephrogenic systemic fibrosis: a mysterious disease in patients with renal failure-role of gadolinium-based contrast media in causation and the beneficial effect of intravenous sodium thiosulfate. Clin J Am Soc Nephrol. 2007;2(2):258–63.17699422
264 Yoldez H, Ahlem B, Abderrahim E, . Nephrogenic fibrosing dermatosis: From clinic to microscopy. Nephrologie et Therapeutique. 2018;14(1):47–49.29239786
265 Zelasko S, Hollingshead M, Castillo M, . CT and MR imaging of progressive dural involvement by nephrogenic systemic fibrosis. AJNR Am J Neuroradiol. 2008;29(10):1880–2.18854445
266 Zhang B, Liang L, Chen W, . An Updated Study to Determine Association between Gadolinium-Based Contrast Agents and Nephrogenic Systemic Fibrosis. PLoS One. 2015;10(6):e0129720.26076348
267 Zhang R, Rose WN. Photopheresis Provides Significant Long-Lasting Benefit in Nephrogenic Systemic Fibrosis. Case Rep Dermatol Med. 2017;2017:3240287.28695022
268 Zou Z, Ma L. Nephrogenic systemic fibrosis: review of 408 biopsy-confirmed cases. Indian J Dermatol. 2011;56(1):65–73.21572796