# APPENDIX C Search Strategies

## MEDLINE (via PubMed)

Search date: 1/7/2019

#1 | “gadolinium”[mesh] OR “gadoterate meglumine”[supplementary concept] OR “gadobutrol”[supplementary concept] OR “gadoteridol”[supplementary concept] OR “gadobenic acid”[supplementary concept] OR gadolinium[tw] OR GBCA[tw] OR GBCAs[tw] OR “gadoterate meglumine”[tw] OR “gadoteric acid”[tw] OR dotarem[tw] OR artirem[tw] OR clariscan[tw] OR gadobutrol[tw] OR gadavist[tw] OR gadovist[tw] OR gadograf[tw] OR gadoteridol[tw] OR prohance[tw] OR “gadobenate dimeglumine”[tw] OR “gadobenic acid”[tw] OR multihance[tw] OR “gadoxetate disodium”[tw] OR “gadoxetic acid”[tw] OR eovist[tw] OR primovist[tw] OR gadograf[tw] | 33,757
#2 | (“contrast media”[mesh] OR “contrast media”[pharmacological action] OR “contrast media”[tw] OR “contrast medium”[tw] OR “contrast agent”[tw] OR “contrast agents”[tw] OR “contrast dye”[tw] OR “contrast dyes”[tw] OR “contrast enhanced”[tw]) AND (“magnetic resonance imaging”[mesh] OR “magnetic resonance imaging, interventional”[mesh] OR “magnetic resonance imaging”[tw] OR “magnetic resonance angiography”[tw] OR MRI[tw] OR MRA[tw]) | 48,810
#3 | #1 OR #2 | 62,787
#4 | "nephrogenic fibrosing dermopathy"[mesh] OR NSF[tw] OR NFD[tw] OR (nephrogenic[tw] AND fibros*[tw]) | 3,809
#5 | #3 AND #4 | 813
#6 | #5 NOT (animals[mesh] NOT humans[mesh]) | 771
#7 | #6 NOT (Editorial[ptyp] OR Comment[ptyp]) | 689
#8 | #7 AND English[lang] | 639

## EMBASE (via Elsevier)

Search date: 1/7/2019

#1 | ‘gadolinium’/exp OR ‘gadoterate meglumine’/exp OR ‘gadoteric acid’/exp OR ‘gadobutrol’/exp OR ‘gadoteridol’/exp OR ‘gadobenic acid’/exp OR ‘gadobenat dimeglumine’/exp OR ‘gadoxetic acid’/exp OR gadolinium:ti,ab,kw OR GBCA:ti,ab,kw OR GBCAs:ti,ab,kw OR ‘gadoterate meglumine’:ti,ab,kw OR ‘gadoteric acid’:ti,ab,kw OR dotarem:ti,ab,kw OR artirem:ti,ab,kw OR clariscan:ti,ab,kw OR gadobutrol:ti,ab,kw OR gadavist:ti,ab,kw OR gadovist:ti,ab,kw OR gadograf:ti,ab,kw OR gadoteridol:ti,ab,kw OR prohance:ti,ab,kw OR ‘gadobenate dimeglumine’:ti,ab,kw OR ‘gadobenic acid’:ti,ab,kw OR multihance:ti,ab,kw OR ‘gadoxetate disodium’:ti,ab,kw OR ‘gadoxetic acid’:ti,ab,kw OR eovist:ti,ab,kw OR primovist:ti,ab,kw OR gadograf:ti,ab,kw | 61,309
#2 | (’contrast media’/exp OR ‘contrast media’:ti,ab,kw OR ‘contrast medium’:ti,ab,kw OR ‘contrast agent’:ti,ab,kw OR ‘contrast agents’:ti,ab,kw OR ‘contrast dye’:ti,ab,kw OR ‘contrast dyes’:ti,ab,kw OR ‘contrast enhanced’:ti,ab,kw) AND (’ nuclear magnetic resonance imaging’/exp OR ‘magnetic resonance imaging’:ti,ab,kw OR ‘magnetic resonance angiography’:ti,ab,kw OR MRI:ti,ab,kw OR MRA:ti,ab,kw) | 72,313
#3 | #1 OR #2 | 119,975
#4 | ‘nephrogenic systemic fibrosis’/exp OR NSF:ti,ab,kw OR NFD:ti,ab,kw OR (nephrogenic:ti,ab,kw AND fibros*:ti,ab,kw) | 5,192
#5 | #3 AND #4 | 1,405
#6 | #5 AND [humans]/lim | 1,242
#7 | #6 NOT (’editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [conference abstract]/lim) | 927
#8 | #7 AND [english]/lim | 853

## Cochrane Register of Controlled Trials (via Wiley)

Search Date Within CENTRAL: 1/7/2019

#1 | [mh “gadolinium”] OR gadolinium OR GBCA OR GBCAs OR “gadoterate meglumine” OR “gadoteric acid” OR dotarem OR artirem OR clariscan OR gadobutrol OR gadavist OR gadovist OR gadograf OR gadoteridol OR prohance OR “gadobenate dimeglumine” OR “gadobenic acid” OR multihance OR “gadoxetate disodium” OR “gadoxetic acid” OR eovist OR primovist OR gadograf | 2,138
#2 | [mh “contrast media”] OR “contrast media” OR “contrast medium” OR “contrast agent” OR “contrast agents” OR “contrast dye” OR “contrast dyes” OR “contrast enhanced” | 5,789
#3 | [mh “magnetic resonance imaging”] OR [mh “magnetic resonance imaging, interventional”] OR “magnetic resonance imaging” OR “magnetic resonance angiography” OR MRI OR MRA | 23,641
#4 | #2 AND #3 | 1,645
#5 | #1 OR #4 | 3,021
#6 | [mh “nephrogenic fibrosing dermopathy”] OR NSF OR NFD | 124
#7 | nephrogenic AND fibros* | 22
#8 | #6 OR #7 | 141
#9 | #5 AND #8 | 18
#10 | #9 limit to Trials | 15

## Web of Science Core Collection (via Clarivate)

Search date: 1/7/2019

#1 | TS=(gadolinium OR GBCA OR GBCAs OR “gadoterate meglumine” OR “gadoteric acid” OR dotarem OR artirem OR clariscan OR gadobutrol OR gadavist OR gadovist OR gadograf OR gadoteridol OR prohance OR “gadobenate dimeglumine” OR “gadobenic acid” OR multihance OR “gadoxetate disodium” OR “gadoxetic acid” OR eovist OR primovist OR gadograf) | 38,662
#2 | TS=(“contrast media” OR “contrast medium” OR “contrast agent” OR “contrast agents” OR “contrast dye” OR “contrast dyes” OR “contrast enhanced”) | 89,925
#3 | TS=(“magnetic resonance imaging” OR “magnetic resonance imaging, interventional” OR “magnetic resonance imaging” OR “magnetic resonance angiography” OR MRI OR MRA) | 410,317
#4 | #2 AND #3 | 35,768
#5 | #1 OR #4 | 66,398
#6 | TS=(nephrogenic AND fibros*) | 2,257
#7 | #5 AND #6 | 1,592
#8 | #7 AND [Restrict to English language] | 1,540
#9 | #8 AND [Restrict to Article OR Review] | 1,355