# APPENDIX B GBCA Guidelines

American College of Radiology – Published in 2018; ACR Manual on Contrast Media. (2018). [PDF] (10th ed.)
Gad Use Recommendation By Patient Population | [underlined: General Guidance]; Group II GBCAs:; - Strongly preferred [over Group I and III] for any patient at risk of NSF; - Informed consent is not recommended (deference made to local practice preferences); - Assessment of renal function with a questionnaire or laboratory testing is optional prior to intravenous administration at standard or lower dosages; - Group II GBCAs should only be administered if deemed necessary by the supervising radiologist, and the lowest dose needed for diagnosis; Group I or III GBCAs:; - Consider patients with any of the following to be at risk for NSF: any form of dialysis, stage 4/5 CKD not on dialysis, AKI; [underlined: At Risk For CKD]; Inpatient; - An eGFR level should be obtained within 2 days prior to planned administration of a group I or group III GBCA; - Assess for the possibility of AKI [independent of eGFR], as eGFR calculation alone has limited accuracy for the detection of AKI; Outpatient; - If receiving group I or III GBCA, screen for conditions/factors that are associated with renal impairment (eg, history of renal disease, kidney transplant, single kidney, kidney surgery, h/o renal cancer, hypertension on medical therapy, diabetes); - Patients identified to be at risk for having reduced renal function should be assessed by laboratory testing (checking results of prior laboratory tests performed within an acceptable time window, and ordering new laboratory tests only if necessary) and calculation of eGFR; - If most recent prior eGFR is 45 or above, and:; *NO risk factors and eGFR >60 or above, then no eGFR required; *WITH risk factors and/or eGFR 45-59, if most recent eGFR is within 6 weeks of the MRI, no new eGFR is needed; otherwise obtain a new eGFR; - If most recent prior eGFR 44 or below, obtain [new] eGFR within 2 days of the MRI study; [underlined: AKI]; - Group I agents should be avoided in patients with known or suspected AKI; - If GBCA is to be administered in this setting, a group II agent is preferred; [underlined: CKD By Stage/GFR]; CKD 1 or 2 (eGFR 60 to 119 ml min/1.73 m^2^); - There is no evidence that patients in these groups are at increased risk of developing NSF. Any GBCA can be administered safely to these patients; CKD 3 (eGFR 30 to 59 mL / min/1.73 m^2^); - NSF developing after GBCA administration to patients with stable eGFR30-59ml/min/1.73m2 is exceedingly rare. No special precautions are necessary in this group; CKD 4 or 5 (eGFR < 30 mL / min/1.73 m^2^) not on chronic dialysis; - Group I agents are contraindicated in this setting. If a GBCA-enhanced MRI study is to be performed, a group II agent should be used; Severe or end-stage CKD(CKD4 or 5, eGFR < 30 mL / min/1.73m^2^) without dialysis; - Patients receiving group I GBCAs should be considered at risk of developing NSF; [underlined: Dialysis]; - Group I GBCAs contraindicated; - Group II GBCAs recommended; - Elective GBCA-enhanced MRI examinations should be performed as closely before hemodialysis as is possible; - Peritoneal dialysis may provide less NSF risk reduction compared to hemodialysis, but this has not been adequately studied; [underlined: Transplant]; - Considered a risk factor for renal impairment as noted above
Canadian Association of Radiologists – Published in 2019; Schieda, N., Maralani, P. J., Hurrell, C., Tsampalieros, A. K., & Hiremath, S. (2019). Updated Clinical Practice Guideline on Use of Gadolinium-Based Contrast Agents in Kidney Disease Issued by the Canadian Association of Radiologists. Canadian Association of Radiologists Journal. doi:10.1016/j.carj.2019.04.001; Schieda, N., Blaichman, J. I., Costa, A. F., Glikstein, R., Hurrell, C., James, M., Maralani, P. J., Shabana, W., Tang, A., Tsampalieros, A., van der Pol, C. B., & Hiremath, S. (2018). Gadolinium-based contrast agents in kidney disease: a comprehensive review and clinical practice guideline issued by the Canadian Association of Radiologists. Canadian Journal of Kidney Health and Disease, 5, 10.1177/2054358118778573 .
Gad Use Recommendation By Patient Population | [underlined: General Guidance]; Outpatient; - Screening for renal function in outpatients with patient questionnaires or serum creatinine at time of ordering GBCA enhanced MRI, scheduling of GBCA enhanced MRI or at the time of GBCA enhanced MRI to identify patients with possible renal dysfunction is no longer recommended when using Group II GBCAs or the Group III agent gadoxetic acid^a^; Inpatient; - Assess for potential AKI regardless of their eGFR, as eGFR is not always representative of renal function in this setting; [underlined: At Risk For CKD]; - Gadodiamide, gadopentetic acid, or gadoversetamide in at-risk patients absolutely contraindicated; [underlined: AKI]; - Should be managed similar to those with eGFR < 30 mL/min/1.73 m^2^; - Delay GBCA administration when possible until renal function stabilizes or ameliorates depending on the patients underlying cause for acute renal dysfunction^a^; - Gadopentetate dimeglumine, gadodiamide, and gadoversetamide remain absolutely contraindicated; - As kidney function is not stable in patients with AKI, risk assessment for NSF should not be made on the basis of eGFR alone; - When administering Group II or III GBCAs informed consent relating to NSF is not necessary; [underlined: CKD By Stage/GFR]; Patients with CKD 1 or 2 (eGFR between 60 and 90 ml min/1.73 m^2^); - No special precautions should be taken in these patients; Patients with CKD 3 (eGFR between 30 and 60 mL / min/1.73 m^2^); - For patients with moderately reduced kidney function, administration of standard doses of GBCA is safe and no additional precautions are necessary; - No need for informed consent^a^; Patients with CKD 4 or 5 (eGFR < 30 mL / min/1.73 m^2^) or Dialysis-Dependent Patients; - Alternative diagnostic tests should be considered before GBCA are prescribed; - Gadopentetate dimeglumine, gadodiamide, and gadoversetamide remain absolutely contraindicated; - When MRI is considered necessary for patient care then gadolinium enhanced examinations using Group II GBCAs (namely macrocyclic GBCA and gadobenate dimeglumine) or the Group III agent gadoxetic acid may be performed without any patient informed consent; [underlined: Dialysis]; - Manage as per patients with CKD 4/5 described above; - Dialysis-dependent patients should receive dialysis; HD should be performed [following] GBCA administration, ideally within 2-3 hours of MRI. However, initiating dialysis or switching from peritoneal to hemodialysis to reduce the risk of NSF is unproven^a^; - Gadopentetate dimeglumine, gadodiamide, and gadoversetamide remain absolutely contraindicated; - When administering Group II or III GBCAs informed consent relating to NSF is not necessary; [underlined: Transplant]; (No specific recommendations)
European Medicines Agency – Published in 2017; Gadolinium-containing contrast agents - European Medicines Agency. (2017). Retrieved from https://www.ema.europa.eu/en/medicines/human/referrals/gadolinium-containing-contrast-agents
Gad Use Recommendation | [underlined: General Guidance]; - Intravenous linear agents gadoxetic acid and gadobenic acid can continue to be used for liver scans because they are taken up in the liver and meet an important diagnostic need; - Gadopentetic acid given intra-articularly (into the joint) can continue to be used for joint scans because the dose of gadolinium used for joint injections is very low; - All other intravenous linear products (gadodiamide, gadopentetic acid and gadoversetamide) should be suspended in the EU; - Macrocyclic agents (gadobutrol, gadoteric acid and gadoteridol) are more stable and have a lower propensity to release gadolinium than linear agents. These products can continue to be used in their current indications but in the lowest doses that enhance images sufficiently and only when unenhanced body scans are not suitable
Kidney Disease: Improving Global Outcomes (KDIGO) – Published in 2013; KDIGO. (2013). KDIGO 2012 clinical practice guideline for the evaluation and management of chronic kidney disease Clinical Practice Guidelines. Retrieved from https://www.guidelinecentral.com/summaries/kdigo-2012-clinical-practice-guideline-for-the-evaluation-and-management-of-chronic-kidney-disease/#section-date
Gad Use Recommendation By Patient Population | [underlined: CKD By Stage/GFR]; - The Work Group recommends not using gadolinium-containing contrast media in people with GFR <15 ml/min/1.73 m2 (GFR category G5) unless there is no alternative appropriate test; - The Work Group suggests that people with a GFR <30 ml/min/1.73 m2 (GFR categories G4–G5) who require gadolinium-containing contrast media are preferentially offered a macrocyclic chelate preparation
US Food and Drug Administration (FDA) – Published in 2018; FDA Center for Drug Evaluation and Research. (2018). New warnings for gadolinium-based contrast agents (GBCAs) for MRI. Retrieved from https://www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-fda-warns-gadolinium-based-contrast-agents-gbcas-are-retained-body; FDA Center for Drug Evaluation and Research. (2018). gadolinium-based contrast agents in patients with kidney dysfunction. Retrieved from https://www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-new-warnings-using-gadolinium-based-contrast-agents-patients-kidney
Gad Use Recommendation By Patient Population | [underlined: General Guidance]; - Gadolinium retention has not been directly linked to adverse health effects in patients with normal kidney function, and we have concluded that the benefit of all approved GBCAs continues to outweigh any potential risks; - Health care professionals should consider the retention characteristics of each agent when choosing a GBCA for patients who may be at higher risk for gadolinium retention (see Table 1 listing GBCAs). These patients include those requiring multiple lifetime doses, pregnant women, children, and patients with inflammatory conditions. Minimize repeated GBCA imaging studies when possible, particularly closely spaced MRI studies. However, do not avoid or defer necessary GBCA MRI scans; - Linear GBCAs result in more retention and retention for a longer time than macrocyclic GBCAs. Gadolinium levels remaining in the body are higher after administration of Omniscan (gadodiamide) or OptiMARK (gadoversetamide) than after Eovist (gadoxetate disodium), Magnevist (gadopentetate dimeglumine), or Multihance (gadobenate dimeglumine). Gadolinium levels in the body are lowest after administration of Dotarem (gadoterate meglumine), Gadavist (gadobutrol), and ProHance (gadoteridol); the gadolinium levels are also similar across these agents; - Avoid use of GBCAs in patients suspected or known to have impaired drug elimination unless the need for the diagnostic information is essential and not available with non-contrasted MRI or other alternative imaging modalities; - Do not repeat administration of any GBCA during a single imaging session; - Record the specific GBCA and the dose administered to a patient; - When administering a GBCA, do not exceed the recommended dose. Prior to any re-administration, allow sufficient time for elimination of the GBCA from the body (eg, multiple half-lives), as described in the Pharmacokinetics section of the labeling. GBCA elimination half-lives are prolonged in patients with renal impairment; for a GBCA that involves significant hepato-biliary elimination, liver dysfunction may also prolong elimination time; - Advise patients with kidney disease to contact a healthcare professional if any of the following symptoms occurs after receiving a GBCA: burning, itching, swelling, scaling, hardening and tightening of the skin; red or dark patches on the skin; stiffness in joints with trouble moving, bending or straightening the arms, hands, legs or feet; pain in the hip bones or ribs; or muscle weakness; - Report any adverse events with GBCAs to FDA’s MedWatch program; Approved Gadolinium-Based Contrast Agents; - Ablavar (gadofosveset trisodium); - Eovist (gadoxetate disodium); - Magnevist (gadopentetate dimeglumine); - Multihance (gadobenate dimeglumine); - Omniscan (gadodiamide); - Optimark (gadoversetamide injection); - Prohance (gadoteridol); [underlined: At Risk For CKD]; - Use the clinical history to screen patients for features of AKI or risk factors for chronically reduced kidney function; [underlined: AKI]; - Screen patients prior to administration of a GBCA to identify those with AKI or chronic, severe, kidney disease. These patients appear to be at highest risk for NSF; - Use the clinical history to screen patients for features of AKI or risk factors for chronically reduced kidney function; - [These] patients [are] at greatest risk for developing NSF after receiving GBCAs [due to] impaired elimination of the drug. Higher than recommended doses or repeat doses of GBCAs also appear to increase the risk for NSF; - Do not use three of the GBCA drugs-Magnevist, Omniscan, and Optimark. These three GBCA drugs are contraindicated in these patients; [underlined: CKD By Stage/GFR]; - Screen patients prior to administration of a GBCA to identify those with AKI or chronic, severe, kidney disease. These patients appear to be at highest risk for NSF; - (eGFR < 30 mL / min/1.73 m^2^) [These] patients [are] at greatest risk for developing NSF after receiving GBCAs [due to] impaired elimination of the drug. Higher than recommended doses or repeat doses of GBCAs also appear to increase the risk for NSF; - Do not use three of the GBCA drugs-Magnevist, Omniscan, and Optimark. These three GBCA drugs are contraindicated in these patients; [underlined: Dialysis]; - For patients receiving hemodialysis, physicians may consider the prompt initiation of hemodialysis following the administration of a GBCA in order to enhance the contrast agent’s elimination from the body. The usefulness of hemodialysis in the prevention of NSF is unknown

a The guidelines have qualifying statements.