# APPENDIX A Postmarketing Reports on NSF Associated with GBCA Exposure

Publication Year | Targeted Class of GBCA or Specific Agents | Patient Population | Summary of Recommendations
2006^a^ | All GBCAs | Patients with advanced kidney failure | First public report of NSF; after exposure to Omniscan
2006^a^ | All GBCAs | Patients with advanced kidney failure | GBCAs should be used only if necessary Consider dialysis after GBCA exposure
2007^b^ | All GBCAs | All patients | Include Boxed Warning on product labelling of all GBCAs indicating NSF risk in patients with severe kidney insufficiency
2010^c^ | Magnevist, Omniscan, and Optimark | Patients with impaired drug elimination (eg, AKI or severe CKD) (eGFR <30 mL/min) | These three GBCAs are contraindicated in these patient subgroups
2010^d^ | All GBCAs | Patients with suspected impaired drug elimination | Avoid use of GBCAs unless alternative imaging modalities are unavailable
2010^d^ | All GBCAs | Patients with suspected impaired drug elimination | Screen for risks for impaired drug elimination, including patients with CKD or AKI
2015^e^ | All GBCAs | All patients | FDA commenced investigations on risks and mechanisms for retention/accumulation of gadolinium in tissues
2017^f^ | All GBCAs | All patients | FDA’s review identified no evidence of adverse effects from gadolinium retention in the brain
2017^g^ | All GBCAs | All patients | A required labelling update indicating gadolinium retention in the Adverse Reactions and Patient Instructions sections

a http://wayback.archive-it.org/7993/20170112033022/http://www.fda.gov/Drugs/DrugSafety/PostmarketDrugSafetyInformationforPatientsandProviders/ucm053112.htm

b http://wayback.archive-it.org/7993/20170112033008/http://www.fda.gov/NewsEvents/Newsroom/PressAnnouncements/2007/ucm108919.htm

c https://wayback.archive-it.org/7993/20180424232219/https://www.fda.gov/Drugs/DrugSafety/ucm223966.htm

d https://www.fda.gov/drugs/drug-safety-and-availability/fda-drug-safety-communication-fda-warns-gadolinium-based-contrast-agents-gbcas-are-retained-body

e https://wayback.archive-it.org/7993/20180424231918/https://www.fda.gov/Drugs/DrugSafety/ucm455386.htm

f https://wayback.archive-it.org/7993/20180424191936/https://www.fda.gov/Drugs/DrugSafety/ucm559007.htm

g https://wayback.archive-it.org/7993/20180424191926/https://www.fda.gov/Drugs/DrugSafety/ucm589213.htm

Abbreviations: AKI=acute kidney injury; CKD=chronic kidney disease; eGFR=estimated glomerular filtration rate; GBCA=gadolinium-based contrast agent; NSF=nephrogenic systemic fibrosis